# APPENDIX E ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE E1 Organ Weights and Organ-Weight-to-Body-Weight Ratios of Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mglkg | 240/120/240 mglkg
Male
n | 27 | 21
Necropsy body wt | 42.3 ± 0.7 | 38.8 ± 1.0^**^
Heart
Absolute | 0.210 ± 0.007^b^ | 0.198 ± 0.006
Relative | 4.799 ± 0.233^b^ | 5.107 ± 0.137
L. and R. Kidney
Absolute | 0.608 ± 0.012 | 0.552 ± 0.016^**^
Relative | 14.404 ± 0.226 | 14.309 ± 0.522
Liver
Absolute | 1.562 ± 0.041 | 1.426 ± 0.038^*^
Relative | 36.854 ± 0.539 | 36.668 ± 0.470
Lung
Absolute | 0.260 ± 0.010 | 0.237 ± 0.012
Relative | 6.183 ± 0.224 | 6.143 ± 0.317
Female
n | 24 | 26
Necropsy body wt | 33.8 ± 1.0 | 32.5 ± 0.8
Heart
Absolute | 0.172 ± 0.007 | 0.165 ± 0.004
Relative | 5.229 ± 0.334 | 5.131 ± 0.160
L. and R. Kidney
Absolute | 0.402 ± 0.006 | 0.369 ± 0.007^**^
Relative | 12.054 ± 0.298 | 11.463 ± 0.252
Liver
Absolute | 1.250 ± 0.030 | 1.253 ± 0.036
Relative | 37.562 ± 1.254 | 38.790 ± 1.059
Lung
Absolute | 0.297 ± 0.043 | 0.232 ± 0.010
Relative | 9.266 ± 1.717 | 7.248 ± 0.349

* Significantly different (P≤0.05) from the 0/0/0 mg/kg group by a t-test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight-ratios (relative weight are given as mg organ weight/g body weight (mean ± standard error).

b n=26

TABLE E2 Organ Weights and Organ-Weight-to-Body-Weight Ratios of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mglkg | 80/40/80 mglkg | 160/80/160 mg/kg | 240/120/240 mg/kg
Male
n | 24 | 21 | 27 | 22
Necropsy body wt | 44.4 ± 0.5 | 42.6 ± 1.0 | 42.3 ± 1.0 | 42.2 ± 0.8
Brain
Absolute | 0.494 ± 0.004 | 0.479 ± 0.004 | 0.486 ± 0.005 | 0.471 ± 0.006^*^
Relative | 11.14 ± 0.10 | 11.37 ± 0.31 | 11.63 ± 0.29 | 11.21 ± 0.20
Heart
Absolute | 0.227 ± 0.007 | 0.209 ± 0.005 | 0.222 ± 0.007 | 0.222 ± 0.008
Relative | 5.12 ± 0.15 | 4.93 ± 0.11 | 5.26 ± 0.13 | 5.24 ± 0.14
L. and R. Kidney
Absolute | 0.714 ± 0.012 | 0.666 ± 0.017 | 0.691 ± 0.018 | 0.657 ± 0.019
Relative | 16.10 ± 0.23 | 15.67 ± 0.28 | 16.33 ± 0.25 | 15.53 ± 0.26
Liver
Absolute | 1.962 ± 0.054 | 1.987 ± 0.088 | 2.013 ± 0.086 | 2.022 ± 0.124
Relative | 44.11 ± 0.92 | 46.22 ± 1.12 | 47.17 ± 1.25 | 47.49 ± 2.48
Female
n | 23 | 23 | 24 | 21
Necropsy body wt | 40.1 ± 1.2 | 36.3 ± 1.5 | 37.9 ± 0.8 | 37.7 ± 1.3
Brain
Absolute | 0.515 ± 0.004 | 0.494 ± 0.006^*^ | 0.496 ± 0.003^*^ | 0.491 ± 0.004^*^
Relative | 13.12 ± 0.43 | 14.09 ± 0.57 | 13.23 ± 0.29 | 13.32 ± 0.50
Heart
Absolute | 0.164 ± 0.004 | 0.168 ± 0.008 | 0.168 ± 0.006 | 0.162 ± 0.005
Relative | 4.15 ± 0.13 | 4.78 ± 0.28 | 4.49 ± 0.20 | 4.36 ± 0.16
L. and R. Kidney
Absolute | 0.463 ± 0.008 | 0.441 ± 0.011 | 0.444 ± 0.007^b^ | 0.445 ± 0.008
Relative | 11.70 ± 0.25 | 12.42 ± 0.41 | 11.79 ± 0.26^b^ | 11.98 ± 0.34
Liver
Absolute | 1.499 ± 0.041 | 1.441 ± 0.046 | 1.508 ± 0.028 | 1.496 ± 0.042
Relative | 37.61 ± 0.67 | 40.29 ± 1.02 | 40.12 ± 0.95 | 40.03 ± 0.92

* Significantly different (P≤0.05) from the 0/0/0 mg/kg group by Dunnett’s test

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight-ratios (relative weight are given as mg organ weight/g body weight (mean ± standard error).

b n=23

TABLE E3 Organ Weights and Organ-Weight-to-Body-Weight Ratios of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

| 0/0 mglkg | 240/40 mglkg
Male
n | 23 | 22
Necropsy body wt | 46.9 ± 0.5 | 44.7 ± 0.8^*^
Brain
Absolute | 0.509 ± 0.004 | 0.489 ± 0.005^**^
Relative | 10.886 ± 0.126 | 10.997 ± 0.188
Heart
Absolute | 0.228 ± 0.006 | 0.227 ± 0.009
Relative | 4.871 ± 0.124 | 5.064 ± 0.171
L. and R. Kidney
Absolute | 0.772 ± 0.017 | 0.713 ± 0.019^*^
Relative | 16.503 ± 0.401 | 15.954 ± 0.319
Liver
Absolute | 2.297 ± 0.066 | 2.362 ± 0.148
Relative | 49.050 ± 1.399 | 52.401 ± 2.845
Female
n | 25 | 23
Necropsy body wt | 40.464 ± 1.119 | 38.748 ± 1.216^*^
Brain
Absolute | 0.533 ± 0.006 | 0.502 ± 0.006^**^
Relative | 13.439 ± 0.424 | 13.199 ± 0.387
Heart
Absolute | 0.186 ± 0.006 | 0.171 ± 0.005^*^
Relative | 4.678 ± 0.181 | 4.467 ± 0.147
L. and R. Kidney
Absolute | 0.474 ± 0.008 | 0.451 ± 0.011
Relative | 11.858 ± 0.268 | 11.765 ± 0.302
Liver
Absolute | 1.567 ± 0.042 | 1.687 ± 0.180
Relative | 38.983 ± 0.834 | 44.225 ± 5.222

* Significantly different (P≤0.05) from the 0/0 mg/kg group by a t-test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight-ratios (relative weight are given as mg organ weight/g body weight (mean ± standard error).