# APPENDIX D BODY WEIGHT ANALYSES

TABLE D1 Tests of Main Effects and Interactions for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

Source of Variation | Numerator Degrees of Freedom | Denominator Degrees of Freedom | F Value | P Value^b^
Male
Postnatal week | 28 | 1,377 | 781.3 | 0.000
Dose | 1 | 51 | 31.6 | 0.000
Postnatal week × dose | 28 | 1,377 | 1.8 | 0.006
Female
Postnatal week | 28 | 1,386 | 449.1 | 0.000
Dose | 1 | 51 | 5.6 | 0.022
Postnatal week × dose | 28 | 1,386 | 0.5 | 0.979

a Statistical analysis by repeated measures ANOVA

b Probability of significant main effect (postnatal week and dose) or significant interaction (postnatal week × dose); significant at P≤0.05

TABLE D2 Overall Trend Tests for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

Contrast of Interest | Estimate | Standard Error | Degrees of Freedom | t Value | P Value^b^
Male
AZT dose; linear trend | −1.2 | 0.52 | 51 | −2.4 | 0.022
Female
AZT dose; linear trend | −2.7 | 0.48 | 51 | −5.6 | 0.000

a Statistical analysis by repeated measures ANOVA

b Probability of significant linear trend using contrasts; significant at P≤0.05

TABLE D3 Summary Statistics by Sex, Time, and Dose for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| | Male | | | Female
Week | AZT Dose (mg/kg) | n | Body Weight (g)^a^ | P Value^b^ | n | Body Weight (g) | P Value
2 | 0/0/0 | 27 | 8.3 ± 0.2 | | 27 | 8.2 ± 0.2
| 240/120/240 | 26 | 7.7 ± 0.2 | 0.020 | 26 | 7.4 ± 0.2 | 0.005
3 | 0/0/0 | 27 | 10.5 ± 0.2 | | 27 | 10.2 ± 0.3
| 240/120/240 | 26 | 9.8 ± 0.2 | 0.026 | 26 | 9.2 ± 0.2 | 0.002
4 | 0/0/0 | 27 | 15.6 ± 0.3 | | 27 | 13.7 ± 0.3
| 240/120/240 | 26 | 14.4 ± 0.3 | 0.004 | 26 | 13.0 ± 0.2 | 0.040
5 | 0/0/0 | 27 | 21.7 ± 0.3 | | 26 | 18.1 ± 0.3
| 240/120/240 | 26 | 20.3 ± 0.3 | 0.000 | 26 | 17.1 ± 0.2 | 0.007
6 | 0/0/0 | 27 | 24.8 ± 0.3 | | 26 | 20.7 ± 0.3
| 240/120/240 | 26 | 23.0 ± 0.2 | 0.000 | 26 | 19.7 ± 0.2 | 0.005
7 | 0/0/0 | 27 | 26.6 ± 0.3 | | 26 | 21.7 ± 0.3
| 240/120/240 | 26 | 24.6 ± 0.2 | 0.000 | 26 | 20.7 ± 0.2 | 0.012
8 | 0/0/0 | 27 | 28.0 ± 0.3 | | 26 | 22.8 ± 0.3
| 240/120/240 | 26 | 26.2 ± 0.2 | 0.000 | 26 | 21.7 ± 0.2 | 0.003
9 | 0/0/0 | 27 | 29.4 ± 0.3 | | 26 | 23.7 ± 0.3
| 240/120/240 | 26 | 27.2 ± 0.3 | 0.000 | 26 | 22.7 ± 0.2 | 0.012
10 | 0/0/0 | 27 | 30.6 ± 0.3 | | 26 | 24.7 ± 0.3
| 240/120/240 | 26 | 28.1 ± 0.3 | 0.000 | 26 | 23.6 ± 0.2 | 0.009
11 | 0/0/0 | 27 | 31.4 ± 0.3 | | 26 | 25.4 ± 0.4
| 240/120/240 | 26 | 29.2 ± 0.3 | 0.000 | 26 | 24.3 ± 0.2 | 0.013
12 | 0/0/0 | 27 | 32.6 ± 0.4 | | 26 | 26.3 ± 0.4
| 240/120/240 | 26 | 29.8 ± 0.4 | 0.000 | 26 | 25.0 ± 0.3 | 0.020
13 | 0/0/0 | 27 | 33.7 ± 0.4 | | 26 | 27.4 ± 0.5
| 240/120/240 | 25 | 31.2 ± 0.4 | 0.000 | 26 | 26.0 ± 0.3 | 0.017
14 | 0/0/0 | 27 | 34.9 ± 0.5 | | 26 | 28.0 ± 0.5
| 240/120/240 | 25 | 32.2 ± 0.4 | 0.000 | 26 | 26.8 ± 0.4 | 0.071
15 | 0/0/0 | 27 | 35.8 ± 0.5 | | 26 | 28.6 ± 0.6
| 240/120/240 | 25 | 33.1 ± 0.5 | 0.000 | 26 | 27.5 ± 0.4 | 0.112
16 | 0/0/0 | 27 | 36.8 ± 0.5 | | 26 | 29.4 ± 0.6
| 240/120/240 | 25 | 33.9 ± 0.5 | 0.000 | 26 | 28.2 ± 0.5 | 0.125
17 | 0/0/0 | 27 | 37.7 ± 0.6 | | 26 | 30.3 ± 0.7
| 240/120/240 | 24 | 34.8 ± 0.5 | 0.000 | 26 | 28.6 ± 0.5 | 0.040
18 | 0/0/0 | 27 | 38.4 ± 0.6 | | 25 | 31.3 ± 0.7
| 240/120/240 | 23 | 35.8 ± 0.5 | 0.000 | 26 | 29.5 ± 0.6 | 0.097
19 | 0/0/0 | 27 | 39.0 ± 0.6 | | 25 | 31.8 ± 0.8
| 240/120/240 | 23 | 36.7 ± 0.6 | 0.002 | 26 | 30.2 ± 0.6 | 0.132
20 | 0/0/0 | 27 | 39.9 ± 0.6 | | 25 | 32.7 ± 0.8
| 240/120/240 | 23 | 37.5 ± 0.6 | 0.002 | 26 | 30.8 ± 0.5 | 0.069
21 | 0/0/0 | 27 | 40.7 ± 0.7 | | 25 | 32.9 ± 0.8
| 240/120/240 | 23 | 38.1 ± 0.6 | 0.001 | 26 | 31.2 ± 0.5 | 0.116
22 | 0/0/0 | 27 | 41.6 ± 0.7 | | 25 | 33.3 ± 0.8
| 240/120/240 | 23 | 38.9 ± 0.6 | 0.001 | 26 | 31.7 ± 0.6 | 0.159
23 | 0/0/0 | 27 | 42.2 ± 0.7 | | 25 | 33.6 ± 0.9
| 240/120/240 | 23 | 39.3 ± 0.6 | 0.001 | 26 | 32.3 ± 0.6 | 0.252
24 | 0/0/0 | 27 | 42.8 ± 0.7 | | 25 | 34.4 ± 0.9
| 240/120/240 | 23 | 39.5 ± 0.7 | 0.001 | 26 | 32.8 ± 0.6 | 0.173
25 | 0/0/0 | 27 | 43.4 ± 0.8 | | 25 | 34.9 ± 0.9
| 240/120/240 | 22 | 40.4 ± 0.7 | 0.001 | 26 | 33.1 ± 0.7 | 0.145
26 | 0/0/0 | 27 | 44.1 ± 0.7 | | 25 | 35.3 ± 0.9
| 240/120/240 | 22 | 40.7 ± 0.7 | 0.000 | 26 | 33.5 ± 0.7 | 0.135
27 | 0/0/0 | 27 | 44.5 ± 0.8 | | 25 | 35.5 ± 0.9
| 240/120/240 | 22 | 41.2 ± 0.7 | 0.000 | 26 | 34.1 ± 0.7 | 0.259
28 | 0/0/0 | 27 | 45.2 ± 0.8 | | 24 | 36.0 ± 1.0
| 240/120/240 | 22 | 41.5 ± 0.7 | 0.000 | 26 | 34.5 ± 0.7 | 0.310
29 | 0/0/0 | 27 | 45.9 ± 0.7 | | 24 | 36.5 ± 1.0
| 240/120/240 | 22 | 41.7 ± 0.7 | 0.000 | 26 | 35.3 ± 0.7 | 0.368
30 | 0/0/0 | 27 | 46.2 ± 0.7 | | 24 | 37.0 ± 1.0
| 240/120/240 | 22 | 41.6 ± 0.8 | 0.000 | 26 | 35.7 ± 0.8 | 0.370

a Mean ± standard error

b Probability of significant difference from 0/0/0 mg/kg group by a t-test using contrasts; significant at P≤0.05

TABLE D4 Tests of Main Effects and Interactions for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

Source of Variation | Numerator Degrees of Freedom | Denominator Degrees of Freedom | F Value | P Value^b^
Male
Postnatal week | 43 | 4,177 | 704.3 | 0.000
Dose | 3 | 104 | 5.3 | 0.002
Postnatal week × dose | 129 | 4,177 | 0.4 | 1.000
Female
Postnatal week | 43 | 4,222 | 495.1 | 0.000
Dose | 3 | 103 | 3.7 | 0.014
Postnatal week × dose | 129 | 4,222 | 0.5 | 1.000

a Statistical analysis by repeated measures ANOVA

b Probability of significant main effect (postnatal week and dose) or significant interaction (postnatal week × dose); significant at P≤0.05

TABLE D5 Overall Trend Tests for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

Contrasts of Interest | Estimate | Standard Error | Degrees of Freedom | t Value | P Value^b^
Male
AZT dose; linear trend | −6.3 | 2.0 | 104 | −3.2 | 0.002
AZT dose; quadratic trend | 0.3 | 0.9 | 104 | 0.4 | 0.700
Female
AZT dose; linear trend | −4.2 | 2.1 | 103 | −2.0 | 0.049
AZT dose; quadratic trend | 1.5 | 0.9 | 103 | 1.6 | 0.113

a Statistical analysis by repeated measures ANOVA

b Probability of significant linear or quadratic trend using contrasts; significant at P≤0.05

TABLE D6 Summary Statistics by Sex, Time, and Dose for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| | Male | | | Female
Week | AZT Dose (mg/kg) | n | Body Weight (g)^a^ | P Value^b^ | n | Body Weight (g) | P Value
2 | 0/0/0 | 27 | 8.0 ± 0.2 | | 26 | 7.9 ± 0.2
| 80/40/80 | 27 | 7.6 ± 0.2 | 0.365 | 27 | 7.3 ± 0.2 | 0.071
| 160/80/160 | 27 | 7.8 ± 0.2 | 0.773 | 27 | 7.7 ± 0.1 | 0.840
| 240/120/240 | 27 | 7.3 ± 0.2 | 0.029 | 27 | 7.7 ± 0.2 | 0.797
3 | 0/0/0 | 27 | 10.3 ± 0.2 | | 26 | 10.0 ± 0.3
| 80/40/80 | 27 | 9.8 ± 0.2 | 0.263 | 27 | 9.2 ± 0.3 | 0.051
| 160/80/160 | 27 | 9.9 ± 0.2 | 0.535 | 27 | 9.6 ± 0.1 | 0.537
| 240/120/240 | 27 | 9.5 ± 0.2 | 0.035 | 27 | 9.7 ± 0.2 | 0.699
4 | 0/0/0 | 27 | 15.2 ± 0.2 | | 26 | 13.8 ± 0.3
| 80/40/80 | 27 | 14.4 ± 0.4 | 0.112 | 27 | 12.7 ± 0.3 | 0.007
| 160/80/160 | 27 | 14.9 ± 0.3 | 0.769 | 27 | 13.5 ± 0.2 | 0.695
| 240/120/240 | 27 | 13.8 ± 0.3 | 0.002 | 27 | 13.2 ± 0.2 | 0.253
5 | 0/0/0 | 27 | 21.1 ± 0.3 | | 26 | 18.0 ± 0.3
| 80/40/80 | 27 | 20.2 ± 0.5 | 0.172 | 26 | 17.0 ± 0.3 | 0.043
| 160/80/160 | 27 | 20.6 ± 0.3 | 0.667 | 27 | 17.6 ± 0.2 | 0.737
| 240/120/240 | 27 | 19.8 ± 0.4 | 0.042 | 27 | 17.2 ± 0.3 | 0.182
6 | 0/0/0 | 27 | 24.1 ± 0.3 | | 26 | 20.6 ± 0.3
| 80/40/80 | 25 | 23.3 ± 0.4 | 0.078 | 26 | 19.6 ± 0.3 | 0.029
| 160/80/160 | 27 | 23.7 ± 0.3 | 0.800 | 27 | 20.2 ± 0.2 | 0.559
| 240/120/240 | 27 | 22.8 ± 0.3 | 0.029 | 27 | 19.8 ± 0.3 | 0.086
7 | 0/0/0 | 27 | 25.8 ± 0.3 | | 26 | 21.8 ± 0.3
| 80/40/80 | 25 | 25.0 ± 0.4 | 0.071 | 26 | 20.5 ± 0.3 | 0.005
| 160/80/160 | 27 | 25.3 ± 0.3 | 0.715 | 27 | 21.2 ± 0.2 | 0.286
| 240/120/240 | 27 | 24.4 ± 0.4 | 0.018 | 26 | 20.9 ± 0.3 | 0.050
8 | 0/0/0 | 27 | 27.5 ± 0.3 | | 26 | 22.8 ± 0.3
| 80/40/80 | 25 | 26.4 ± 0.4 | 0.033 | 26 | 21.7 ± 0.3 | 0.030
| 160/80/160 | 27 | 26.9 ± 0.4 | 0.505 | 27 | 22.1 ± 0.2 | 0.268
| 240/120/240 | 27 | 26.0 ± 0.4 | 0.014 | 26 | 21.9 ± 0.3 | 0.089
9 | 0/0/0 | 27 | 28.7 ± 0.4 | | 26 | 23.7 ± 0.4
| 80/40/80 | 25 | 27.7 ± 0.4 | 0.096 | 26 | 22.7 ± 0.4 | 0.131
| 160/80/160 | 27 | 28.2 ± 0.4 | 0.757 | 27 | 23.1 ± 0.3 | 0.514
| 240/120/240 | 27 | 27.1 ± 0.4 | 0.020 | 26 | 22.9 ± 0.4 | 0.237
10 | 0/0/0 | 27 | 29.8 ± 0.4 | | 26 | 24.7 ± 0.4
| 80/40/80 | 25 | 28.8 ± 0.5 | 0.092 | 26 | 23.7 ± 0.4 | 0.120
| 160/80/160 | 27 | 29.3 ± 0.4 | 0.677 | 27 | 24.2 ± 0.2 | 0.713
| 240/120/240 | 27 | 27.8 ± 0.4 | 0.003 | 26 | 23.8 ± 0.4 | 0.156
11 | 0/0/0 | 27 | 31.0 ± 0.5 | | 26 | 25.8 ± 0.4
| 80/40/80 | 24 | 30.1 ± 0.5 | 0.191 | 26 | 24.6 ± 0.4 | 0.078
| 160/80/160 | 27 | 30.3 ± 0.5 | 0.579 | 27 | 25.0 ± 0.2 | 0.303
| 240/120/240 | 27 | 28.7 ± 0.4 | 0.002 | 26 | 25.0 ± 0.4 | 0.291
12 | 0/0/0 | 26 | 32.1 ± 0.5 | | 26 | 26.6 ± 0.5
| 80/40/80 | 24 | 31.0 ± 0.6 | 0.242 | 26 | 25.6 ± 0.4 | 0.213
| 160/80/160 | 27 | 31.5 ± 0.5 | 0.817 | 27 | 26.0 ± 0.3 | 0.593
| 240/120/240 | 27 | 29.6 ± 0.5 | 0.003 | 26 | 25.6 ± 0.5 | 0.181
13 | 0/0/0 | 26 | 33.3 ± 0.5 | | 26 | 27.5 ± 0.5
| 80/40/80 | 24 | 32.1 ± 0.6 | 0.250 | 26 | 26.0 ± 0.5 | 0.050
| 160/80/160 | 27 | 32.6 ± 0.5 | 0.796 | 27 | 26.7 ± 0.3 | 0.409
| 240/120/240 | 26 | 30.4 ± 0.6 | 0.002 | 26 | 26.4 ± 0.5 | 0.187
14 | 0/0/0 | 26 | 34.4 ± 0.5 | | 26 | 28.4 ± 0.6
| 80/40/80 | 24 | 32.9 ± 0.6 | 0.152 | 26 | 26.8 ± 0.5 | 0.049
| 160/80/160 | 27 | 33.6 ± 0.6 | 0.775 | 27 | 27.3 ± 0.3 | 0.229
| 240/120/240 | 25 | 31.5 ± 0.6 | 0.002 | 26 | 27.3 ± 0.6 | 0.203
15 | 0/0/0 | 26 | 35.5 ± 0.6 | | 26 | 29.6 ± 0.6
| 80/40/80 | 24 | 33.8 ± 0.7 | 0.129 | 26 | 27.5 ± 0.6 | 0.013
| 160/80/160 | 27 | 34.6 ± 0.6 | 0.723 | 27 | 28.2 ± 0.4 | 0.157
| 240/120/240 | 25 | 32.6 ± 0.6 | 0.003 | 26 | 28.0 ± 0.6 | 0.076
16 | 0/0/0 | 26 | 36.3 ± 0.6 | | 26 | 30.3 ± 0.7
| 80/40/80 | 24 | 34.6 ± 0.7 | 0.161 | 26 | 28.4 ± 0.7 | 0.056
| 160/80/160 | 27 | 35.4 ± 0.7 | 0.761 | 27 | 28.8 ± 0.4 | 0.167
| 240/120/240 | 25 | 33.4 ± 0.7 | 0.006 | 26 | 28.6 ± 0.6 | 0.114
17 | 0/0/0 | 26 | 37.3 ± 0.6 | | 26 | 31.1 ± 0.7
| 80/40/80 | 24 | 35.3 ± 0.8 | 0.101 | 26 | 29.0 ± 0.8 | 0.067
| 160/80/160 | 27 | 36.4 ± 0.7 | 0.796 | 27 | 29.6 ± 0.4 | 0.250
| 240/120/240 | 25 | 34.3 ± 0.7 | 0.006 | 26 | 29.3 ± 0.6 | 0.116
18 | 0/0/0 | 26 | 38.1 ± 0.6 | | 26 | 31.8 ± 0.7
| 80/40/80 | 24 | 36.1 ± 0.8 | 0.102 | 26 | 29.8 ± 0.8 | 0.084
| 160/80/160 | 27 | 37.3 ± 0.8 | 0.826 | 27 | 30.2 ± 0.5 | 0.194
| 240/120/240 | 25 | 35.1 ± 0.7 | 0.009 | 26 | 29.9 ± 0.7 | 0.108
19 | 0/0/0 | 26 | 38.9 ± 0.6 | | 26 | 32.7 ± 0.8
| 80/40/80 | 24 | 36.8 ± 0.8 | 0.098 | 26 | 30.5 ± 0.8 | 0.084
| 160/80/160 | 27 | 38.0 ± 0.8 | 0.784 | 27 | 30.9 ± 0.5 | 0.175
| 240/120/240 | 25 | 35.9 ± 0.8 | 0.014 | 26 | 30.6 ± 0.8 | 0.098
20 | 0/0/0 | 26 | 39.8 ± 0.6 | | 26 | 33.1 ± 0.8
| 80/40/80 | 24 | 37.2 ± 0.9 | 0.048 | 26 | 30.8 ± 0.8 | 0.076
| 160/80/160 | 27 | 38.6 ± 0.8 | 0.630 | 27 | 31.5 ± 0.5 | 0.274
| 240/120/240 | 25 | 36.6 ± 0.8 | 0.012 | 26 | 31.3 ± 0.8 | 0.198
21 | 0/0/0 | 26 | 40.5 ± 0.7 | | 26 | 33.7 ± 0.8
| 80/40/80 | 24 | 37.9 ± 0.9 | 0.062 | 26 | 31.5 ± 0.9 | 0.112
| 160/80/160 | 27 | 39.2 ± 0.9 | 0.592 | 27 | 32.2 ± 0.5 | 0.395
| 240/120/240 | 25 | 37.6 ± 0.8 | 0.029 | 26 | 31.7 ± 0.8 | 0.169
22 | 0/0/0 | 26 | 40.9 ± 0.7 | | 26 | 34.5 ± 0.8
| 80/40/80 | 24 | 38.8 ± 0.9 | 0.178 | 26 | 32.1 ± 1.0 | 0.081
| 160/80/160 | 27 | 40.1 ± 0.9 | 0.890 | 27 | 32.8 ± 0.6 | 0.287
| 240/120/240 | 25 | 38.2 ± 0.8 | 0.068 | 26 | 32.2 ± 0.8 | 0.109
23 | 0/0/0 | 25 | 41.8 ± 0.7 | | 26 | 34.8 ± 0.9
| 80/40/80 | 24 | 39.4 ± 1.0 | 0.176 | 26 | 32.6 ± 1.0 | 0.146
| 160/80/160 | 27 | 40.6 ± 0.9 | 0.828 | 27 | 33.1 ± 0.6 | 0.349
| 240/120/240 | 25 | 38.8 ± 0.8 | 0.067 | 26 | 32.9 ± 0.8 | 0.255
24 | 0/0/0 | 25 | 42.2 ± 0.8 | | 26 | 35.0 ± 0.9
| 80/40/80 | 24 | 40.0 ± 1.0 | 0.282 | 26 | 33.0 ± 1.0 | 0.197
| 160/80/160 | 27 | 41.0 ± 1.0 | 0.828 | 26 | 34.1 ± 0.6 | 0.637
| 240/120/240 | 25 | 39.4 ± 0.8 | 0.119 | 26 | 33.4 ± 0.9 | 0.374
25 | 0/0/0 | 25 | 42.8 ± 0.8 | | 26 | 35.1 ± 1.0
| 80/40/80 | 24 | 40.6 ± 1.0 | 0.281 | 26 | 33.4 ± 1.0 | 0.413
| 160/80/160 | 27 | 41.5 ± 1.0 | 0.785 | 26 | 34.4 ± 0.7 | 0.792
| 240/120/240 | 25 | 40.1 ± 0.8 | 0.149 | 26 | 33.7 ± 0.9 | 0.556
26 | 0/0/0 | 25 | 43.4 ± 0.7 | | 26 | 35.3 ± 1.1
| 80/40/80 | 24 | 41.2 ± 1.0 | 0.290 | 26 | 33.9 ± 1.0 | 0.583
| 160/80/160 | 27 | 42.1 ± 1.0 | 0.772 | 26 | 34.6 ± 0.7 | 0.821
| 240/120/240 | 25 | 40.8 ± 0.9 | 0.176 | 26 | 34.2 ± 0.9 | 0.737
27 | 0/0/0 | 25 | 44.0 ± 0.8 | | 25 | 36.4 ± 1.0
| 80/40/80 | 24 | 41.7 ± 1.0 | 0.245 | 26 | 34.3 ± 1.0 | 0.446
| 160/80/160 | 27 | 42.4 ± 1.0 | 0.593 | 25 | 35.3 ± 0.6 | 0.666
| 240/120/240 | 25 | 41.1 ± 0.9 | 0.096 | 26 | 34.7 ± 1.0 | 0.652
28 | 0/0/0 | 25 | 44.4 ± 0.7 | | 25 | 36.8 ± 1.0
| 80/40/80 | 24 | 42.3 ± 1.1 | 0.273 | 26 | 34.7 ± 1.1 | 0.405
| 160/80/160 | 27 | 42.9 ± 1.0 | 0.601 | 25 | 35.7 ± 0.6 | 0.696
| 240/120/240 | 25 | 41.5 ± 0.8 | 0.093 | 26 | 35.1 ± 1.0 | 0.617
29 | 0/0/0 | 25 | 44.9 ± 0.7 | | 25 | 37.0 ± 1.0
| 80/40/80 | 24 | 42.9 ± 1.0 | 0.343 | 26 | 35.2 ± 1.1 | 0.567
| 160/80/160 | 27 | 43.3 ± 1.0 | 0.544 | 25 | 36.0 ± 0.6 | 0.759
| 240/120/240 | 25 | 42.0 ± 0.8 | 0.089 | 26 | 35.3 ± 1.0 | 0.618
30 | 0/0/0 | 25 | 45.3 ± 0.7 | | 25 | 37.9 ± 1.1
| 80/40/80 | 24 | 43.1 ± 1.0 | 0.255 | 26 | 35.5 ± 1.1 | 0.354
| 160/80/160 | 27 | 43.6 ± 1.0 | 0.474 | 25 | 36.6 ± 0.6 | 0.687
| 240/120/240 | 25 | 42.3 ± 0.9 | 0.083 | 26 | 35.8 ± 1.0 | 0.444
31 | 0/0/0 | 25 | 45.5 ± 0.7 | | 25 | 38.1 ± 1.1
| 80/40/80 | 24 | 43.3 ± 1.1 | 0.268 | 25 | 35.8 ± 1.2 | 0.294
| 160/80/160 | 27 | 43.9 ± 1.0 | 0.537 | 25 | 36.5 ± 0.6 | 0.504
| 240/120/240 | 25 | 42.4 ± 0.8 | 0.062 | 26 | 36.1 ± 1.0 | 0.481
32 | 0/0/0 | 25 | 45.3 ± 0.7 | | 25 | 38.6 ± 1.0
| 80/40/80 | 23 | 43.8 ± 1.1 | 0.495 | 25 | 36.3 ± 1.1 | 0.272
| 160/80/160 | 27 | 44.1 ± 1.0 | 0.787 | 25 | 37.2 ± 0.6 | 0.576
| 240/120/240 | 25 | 42.6 ± 0.9 | 0.135 | 26 | 36.6 ± 1.0 | 0.408
33 | 0/0/0 | 24 | 45.5 ± 0.7 | | 25 | 38.6 ± 1.1
| 80/40/80 | 23 | 44.1 ± 1.1 | 0.708 | 25 | 36.7 ± 1.2 | 0.451
| 160/80/160 | 27 | 44.5 ± 1.0 | 0.958 | 25 | 37.7 ± 0.6 | 0.837
| 240/120/240 | 24 | 43.1 ± 0.9 | 0.242 | 26 | 36.6 ± 1.1 | 0.465
34 | 0/0/0 | 24 | 45.8 ± 0.7 | | 25 | 39.2 ± 1.2
| 80/40/80 | 23 | 44.5 ± 1.1 | 0.675 | 25 | 36.4 ± 1.3 | 0.209
| 160/80/160 | 27 | 44.7 ± 1.0 | 0.890 | 25 | 38.0 ± 0.6 | 0.759
| 240/120/240 | 24 | 43.5 ± 0.9 | 0.231 | 26 | 36.8 ± 1.1 | 0.344
35 | 0/0/0 | 24 | 46.4 ± 0.7 | | 25 | 39.6 ± 1.1
| 80/40/80 | 23 | 45.0 ± 1.1 | 0.654 | 25 | 36.7 ± 1.3 | 0.189
| 160/80/160 | 27 | 45.2 ± 1.0 | 0.859 | 25 | 38.7 ± 0.6 | 0.881
| 240/120/240 | 24 | 43.8 ± 0.9 | 0.151 | 25 | 37.1 ± 1.2 | 0.254
36 | 0/0/0 | 24 | 46.9 ± 0.6 | | 25 | 39.9 ± 1.2
| 80/40/80 | 23 | 45.1 ± 1.1 | 0.429 | 25 | 37.0 ± 1.3 | 0.172
| 160/80/160 | 27 | 45.4 ± 0.9 | 0.635 | 25 | 39.1 ± 0.7 | 0.900
| 240/120/240 | 24 | 44.2 ± 0.8 | 0.105 | 25 | 37.5 ± 1.1 | 0.293
37 | 0/0/0 | 24 | 47.2 ± 0.6 | | 25 | 40.2 ± 1.3
| 80/40/80 | 23 | 45.2 ± 1.1 | 0.288 | 25 | 37.2 ± 1.3 | 0.168
| 160/80/160 | 27 | 45.7 ± 0.9 | 0.636 | 25 | 39.2 ± 0.6 | 0.864
| 240/120/240 | 24 | 44.7 ± 0.8 | 0.153 | 25 | 37.7 ± 1.1 | 0.277
38 | 0/0/0 | 24 | 47.5 ± 0.6 | | 25 | 40.7 ± 1.3
| 80/40/80 | 22 | 45.5 ± 1.1 | 0.302 | 25 | 37.6 ± 1.3 | 0.162
| 160/80/160 | 27 | 46.0 ± 0.9 | 0.637 | 25 | 39.4 ± 0.7 | 0.743
| 240/120/240 | 24 | 44.9 ± 0.9 | 0.150 | 25 | 38.0 ± 1.2 | 0.221
39 | 0/0/0 | 24 | 47.9 ± 0.6 | | 24 | 41.6 ± 1.3
| 80/40/80 | 22 | 45.9 ± 1.1 | 0.296 | 25 | 38.3 ± 1.3 | 0.191
| 160/80/160 | 27 | 46.1 ± 0.9 | 0.448 | 25 | 39.8 ± 0.7 | 0.709
| 240/120/240 | 24 | 45.3 ± 0.9 | 0.139 | 25 | 38.3 ± 1.2 | 0.174
40 | 0/0/0 | 24 | 48.0 ± 0.6 | | 24 | 41.7 ± 1.1
| 80/40/80 | 22 | 46.3 ± 1.2 | 0.373 | 25 | 38.2 ± 1.4 | 0.115
| 160/80/160 | 27 | 46.4 ± 0.9 | 0.497 | 25 | 40.1 ± 0.6 | 0.739
| 240/120/240 | 24 | 45.6 ± 0.8 | 0.155 | 23 | 39.3 ± 1.2 | 0.195
41 | 0/0/0 | 24 | 48.4 ± 0.6 | | 24 | 42.3 ± 1.2
| 80/40/80 | 22 | 46.3 ± 1.1 | 0.229 | 24 | 38.1 ± 1.3 | 0.047
| 160/80/160 | 27 | 46.6 ± 0.9 | 0.376 | 25 | 40.8 ± 0.6 | 0.773
| 240/120/240 | 22 | 45.9 ± 0.8 | 0.140 | 22 | 39.3 ± 1.3 | 0.109
42 | 0/0/0 | 24 | 48.5 ± 0.6 | | 23 | 42.6 ± 1.3
| 80/40/80 | 22 | 46.4 ± 1.1 | 0.205 | 24 | 38.4 ± 1.5 | 0.091
| 160/80/160 | 27 | 47.0 ± 0.9 | 0.499 | 25 | 40.9 ± 0.8 | 0.812
| 240/120/240 | 22 | 45.9 ± 0.8 | 0.117 | 21 | 39.9 ± 1.2 | 0.191
43 | 0/0/0 | 24 | 48.9 ± 0.6 | | 23 | 43.2 ± 1.3
| 80/40/80 | 22 | 46.5 ± 1.1 | 0.164 | 24 | 38.4 ± 1.5 | 0.039
| 160/80/160 | 27 | 47.2 ± 0.9 | 0.465 | 24 | 40.6 ± 0.8 | 0.462
| 240/120/240 | 22 | 46.2 ± 0.8 | 0.125 | 21 | 40.5 ± 1.3 | 0.202
44 | 0/0/0 | 24 | 49.2 ± 0.5 | | 23 | 43.6 ± 1.3
| 80/40/80 | 22 | 46.5 ± 1.2 | 0.077 | 24 | 38.5 ± 1.5 | 0.019
| 160/80/160 | 27 | 47.1 ± 0.9 | 0.240 | 24 | 40.9 ± 0.7 | 0.411
| 240/120/240 | 22 | 46.4 ± 0.8 | 0.093 | 21 | 40.7 ± 1.3 | 0.167
45 | 0/0/0 | 24 | 49.2 ± 0.5 | | 23 | 43.3 ± 1.3
| 80/40/80 | 22 | 46.7 ± 1.1 | 0.127 | 23 | 39.7 ± 1.6 | 0.105
| 160/80/160 | 27 | 46.9 ± 1.0 | 0.199 | 24 | 41.2 ± 0.7 | 0.623
| 240/120/240 | 22 | 46.3 ± 0.9 | 0.091 | 21 | 41.1 ± 1.3 | 0.385

a Mean ± standard error

b Probability of significant difference from 0/0/0 mg/kg group by a Dunnett’s test using contrasts; significant at P≤0.05

TABLE D7 Tests of Main Effects and Interactions for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

Source of Variation | Numerator Degrees of Freedom | Denominator Degrees of Freedom | F Value | P Value^b^
Male
Postnatal week | 43 | 1,939 | 539.9 | 0.000
Dose | 1 | 46 | 5.7 | 0.022
Postnatal week × dose | 43 | 1,939 | 1.2 | 0.205
Female
Postnatal week | 43 | 2,095 | 232.8 | 0.000
Dose | 1 | 50 | 2.9 | 0.097
Postnatal week × dose | 43 | 2,095 | 1.3 | 0.071

a Statistical analysis by repeated measures ANOVA

b Probability of significant main effect (postnatal week and dose) or significant interaction (postnatal week × dose); significant at P≤0.05

TABLE D8 Overall Trend Tests for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

Contrast of Interest | Estimate | Standard Error | Degrees of Freedom | t Value | P Value^b^
Male
AZT dose; linear trend | −1.3 | 0.55 | 46 | −2.4 | 0.022
Female
AZT dose; linear trend | −1.2 | 0.69 | 50 | −1.7 | 0.097

a Statistical analysis by repeated measures ANOVA

b Probability of significant linear trend using contrasts; significant at P≤0.05

TABLE D9 Summary Statistics by Sex, Time, and Dose for Body Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| | Male | | | Female
Week | AZT Dose (mg/kg) | n | Body Weight (g)^a^ | P Value^b^ | n | Body Weight (g) | P Value
2 | 0/0 | 24 | 8.1 ± 0.2 | | 26 | 8.1 ± 0.2
| 240/40 | 24 | 7.6 ± 0.2 | 0.133 | 26 | 7.4 ± 0.3 | 0.033
3 | 0/0 | 24 | 10.2 ± 0.2 | | 26 | 10.2 ± 0.2
| 240/40 | 24 | 9.6 ± 0.3 | 0.099 | 26 | 9.1 ± 0.3 | 0.009
4 | 0/0 | 24 | 15.1 ± 0.3 | | 26 | 14.2 ± 0.2
| 240/40 | 24 | 14.4 ± 0.4 | 0.191 | 26 | 13.1 ± 0.4 | 0.009
5 | 0/0 | 24 | 21.3 ± 0.4 | | 26 | 19.0 ± 0.3
| 240/40 | 24 | 21.0 ± 0.5 | 0.671 | 26 | 17.9 ± 0.4 | 0.033
6 | 0/0 | 24 | 24.4 ± 0.2 | | 26 | 21.2 ± 0.3
| 240/40 | 24 | 23.7 ± 0.4 | 0.093 | 26 | 20.3 ± 0.4 | 0.058
7 | 0/0 | 24 | 26.8 ± 0.3 | | 26 | 22.3 ± 0.2
| 240/40 | 24 | 25.8 ± 0.4 | 0.031 | 26 | 21.4 ± 0.4 | 0.040
8 | 0/0 | 24 | 28.4 ± 0.3 | | 26 | 23.2 ± 0.3
| 240/40 | 24 | 27.4 ± 0.4 | 0.045 | 26 | 22.8 ± 0.4 | 0.346
9 | 0/0 | 24 | 30.2 ± 0.3 | | 26 | 24.5 ± 0.3
| 240/40 | 24 | 28.8 ± 0.5 | 0.012 | 26 | 23.9 ± 0.5 | 0.293
10 | 0/0 | 24 | 30.5 ± 0.4 | | 26 | 25.3 ± 0.4
| 240/40 | 24 | 29.7 ± 0.5 | 0.248 | 26 | 24.4 ± 0.5 | 0.147
11 | 0/0 | 24 | 31.3 ± 0.4 | | 26 | 25.9 ± 0.3
| 240/40 | 24 | 30.6 ± 0.5 | 0.249 | 26 | 25.4 ± 0.5 | 0.404
12 | 0/0 | 24 | 32.4 ± 0.4 | | 26 | 26.5 ± 0.4
| 240/40 | 24 | 30.9 ± 0.6 | 0.046 | 26 | 25.6 ± 0.6 | 0.224
13 | 0/0 | 24 | 32.8 ± 0.4 | | 26 | 26.3 ± 0.3
| 240/40 | 24 | 32.2 ± 0.6 | 0.433 | 26 | 26.2 ± 0.6 | 1.000
14 | 0/0 | 24 | 34.6 ± 0.5 | | 26 | 28.0 ± 0.4
| 240/40 | 24 | 33.5 ± 0.7 | 0.212 | 26 | 27.6 ± 0.6 | 0.515
15 | 0/0 | 24 | 36.2 ± 0.6 | | 26 | 28.8 ± 0.5
| 240/40 | 24 | 34.8 ± 0.7 | 0.125 | 26 | 28.7 ± 0.6 | 1.000
16 | 0/0 | 24 | 36.7 ± 0.5 | | 26 | 29.0 ± 0.6
| 240/40 | 24 | 35.8 ± 0.8 | 0.345 | 26 | 28.7 ± 0.7 | 0.794
17 | 0/0 | 24 | 37.8 ± 0.5 | | 26 | 30.1 ± 0.7
| 240/40 | 24 | 37.1 ± 0.8 | 0.496 | 26 | 28.8 ± 0.7 | 0.181
18 | 0/0 | 24 | 39.0 ± 0.6 | | 26 | 30.6 ± 0.7
| 240/40 | 24 | 37.6 ± 0.9 | 0.196 | 26 | 30.1 ± 0.8 | 0.597
19 | 0/0 | 24 | 39.9 ± 0.5 | | 26 | 31.1 ± 0.7
| 240/40 | 24 | 38.9 ± 0.9 | 0.350 | 26 | 30.8 ± 0.8 | 1.000
20 | 0/0 | 24 | 40.9 ± 0.5 | | 26 | 32.0 ± 0.8
| 240/40 | 24 | 39.9 ± 0.9 | 0.356 | 26 | 31.6 ± 0.8 | 0.733
21 | 0/0 | 24 | 41.3 ± 0.6 | | 26 | 32.7 ± 0.7
| 240/40 | 24 | 40.6 ± 0.9 | 0.502 | 26 | 32.1 ± 0.8 | 0.565
22 | 0/0 | 24 | 42.6 ± 0.5 | | 26 | 33.3 ± 0.8
| 240/40 | 24 | 41.4 ± 1.0 | 0.294 | 26 | 32.9 ± 0.8 | 0.683
23 | 0/0 | 24 | 44.0 ± 0.6 | | 26 | 33.9 ± 0.9
| 240/40 | 24 | 42.6 ± 0.9 | 0.223 | 26 | 33.2 ± 0.8 | 0.552
24 | 0/0 | 24 | 44.1 ± 0.7 | | 26 | 35.1 ± 0.9
| 240/40 | 19 | 42.5 ± 1.1 | 0.253 | 21 | 33.3 ± 1.0 | 0.209
25 | 0/0 | 24 | 45.2 ± 0.6 | | 26 | 35.3 ± 0.9
| 240/40 | 24 | 43.7 ± 1.0 | 0.193 | 26 | 34.4 ± 0.9 | 0.498
26 | 0/0 | 24 | 45.9 ± 0.6 | | 26 | 35.1 ± 0.9
| 240/40 | 24 | 44.6 ± 0.9 | 0.237 | 26 | 35.4 ± 0.9 | 0.795
27 | 0/0 | 24 | 46.5 ± 0.6 | | 26 | 35.9 ± 0.9
| 240/40 | 24 | 44.8 ± 1.0 | 0.138 | 26 | 36.0 ± 1.1 | 1.000
28 | 0/0 | 24 | 47.2 ± 0.5 | | 26 | 36.7 ± 1.0
| 240/40 | 24 | 45.5 ± 0.9 | 0.118 | 26 | 35.4 ± 1.0 | 0.347
29 | 0/0 | 24 | 47.5 ± 0.6 | | 26 | 36.8 ± 1.0
| 240/40 | 24 | 45.7 ± 0.9 | 0.113 | 26 | 35.9 ± 1.0 | 0.521
30 | 0/0 | 24 | 47.9 ± 0.7 | | 26 | 37.7 ± 1.0
| 240/40 | 24 | 46.6 ± 0.8 | 0.232 | 26 | 37.1 ± 1.1 | 0.715
31 | 0/0 | 24 | 48.4 ± 0.8 | | 26 | 38.6 ± 1.0
| 240/40 | 24 | 47.0 ± 0.8 | 0.222 | 26 | 37.5 ± 1.0 | 0.440
32 | 0/0 | 24 | 48.5 ± 0.9 | | 26 | 39.6 ± 1.1
| 240/40 | 24 | 47.3 ± 0.8 | 0.324 | 26 | 37.7 ± 1.1 | 0.222
33 | 0/0 | 24 | 48.6 ± 1.1 | | 26 | 39.8 ± 1.0
| 240/40 | 24 | 47.7 ± 0.8 | 0.495 | 25 | 38.8 ± 1.0 | 0.329
34 | 0/0 | 23 | 50.0 ± 0.5 | | 26 | 40.6 ± 1.1
| 240/40 | 24 | 47.6 ± 0.8 | 0.055 | 25 | 39.6 ± 1.0 | 0.342
35 | 0/0 | 23 | 50.3 ± 0.5 | | 26 | 41.3 ± 1.0
| 240/40 | 24 | 48.0 ± 0.8 | 0.062 | 25 | 39.6 ± 1.2 | 0.184
36 | 0/0 | 23 | 50.7 ± 0.5 | | 26 | 41.6 ± 1.1
| 240/40 | 24 | 48.3 ± 0.9 | 0.060 | 25 | 39.6 ± 1.2 | 0.151
37 | 0/0 | 23 | 51.0 ± 0.4 | | 25 | 41.7 ± 1.2
| 240/40 | 24 | 48.2 ± 0.8 | 0.013 | 24 | 41.0 ± 1.1 | 0.331
38 | 0/0 | 23 | 51.1 ± 0.4 | | 25 | 42.0 ± 1.1
| 240/40 | 24 | 48.2 ± 0.9 | 0.011 | 24 | 40.1 ± 1.2 | 0.085
39 | 0/0 | 23 | 51.1 ± 0.5 | | 25 | 42.0 ± 1.2
| 240/40 | 24 | 48.8 ± 0.9 | 0.069 | 24 | 40.7 ± 1.2 | 0.210
40 | 0/0 | 23 | 51.5 ± 0.5 | | 25 | 43.0 ± 1.2
| 240/40 | 23 | 49.2 ± 0.9 | 0.075 | 24 | 40.9 ± 1.1 | 0.088
41 | 0/0 | 23 | 51.7 ± 0.5 | | 25 | 43.1 ± 1.2
| 240/40 | 23 | 49.0 ± 0.9 | 0.027 | 24 | 40.9 ± 1.2 | 0.094
42 | 0/0 | 23 | 51.4 ± 0.5 | | 25 | 43.6 ± 1.2
| 240/40 | 23 | 49.0 ± 0.8 | 0.037 | 23 | 41.1 ± 1.2 | 0.056
43 | 0/0 | 23 | 51.8 ± 0.5 | | 25 | 43.9 ± 1.1
| 240/40 | 22 | 50.0 ± 0.9 | 0.142 | 23 | 41.9 ± 1.3 | 0.120
44 | 0/0 | 23 | 52.1 ± 0.6 | | 25 | 44.2 ± 1.2
| 240/40 | 22 | 50.0 ± 0.9 | 0.065 | 23 | 42.4 ± 1.2 | 0.154
45 | 0/0 | 18 | 52.1 ± 0.7 | | 17 | 45.4 ± 1.5
| 240/40 | 14 | 49.0 ± 1.1 | 0.106 | 16 | 41.3 ± 1.5 | 0.207

a Mean ± standard error. Statistical tests were performed on rounded data.

b Probability of significant difference from 0/0 mg/kg group by a t-test; significant at P≤0.05