# APPENDIX C CLINICAL PATHOLOGY RESULTS

TABLE C1 Hematology and Clinical Chemistry for Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 240/120/240 mg/kg
Male
Hematology
n | 27 | 20
Erythrocytes (10^6^/mm^3^) | 9.8 ± 0.2 | 9.2 ± 0.2^*^
Hemoglobin (g/dL) | 16.1 ± 0.1 | 16.1 ± 0.2
Hematocrit (%) | 47.0 ± 0.9 | 46.3 ± 1.0
Mean cell volume (fL) | 48.0 ± 0.3 | 50.7 ± 0.3^**^
Mean cell hemoglobin (pg) | 16.6 ± 0.4 | 17.7 ± 0.4
Mean cell hemoglobin concentration (g/dL) | 34.0 ± 1.2 | 35.0 ± 0.9
Leukocytes (10^3^/mm^3^) | 2.8 ± 0.3 | 3.1 ± 0.3
Neutrophils (%) | 5.1 ± 0.4 | 5.8 ± 0.6
Lymphocytes (%) | 89.0 ± 0.8 | 86.1 ± 1.7
Monocytes (%) | 6.3 ± 1.8 | 6.0 ± 1.1
Eosinophils (%) | 0.6 ± 0.2 | 0.9 ± 0.2
Basophils (%) | 0.7 ± 0.1 | 1.3 ± 0.2^*^
Platelets (10^3^/mm^3^) | 884.4 ± 25.3 | 810.9 ± 48.6
Clinical Chemistry
n | 25 | 21
Creatinine (mg/dL) | 0.8 ± 0.1 | 0.6 ± 0.1
Blood urea nitrogen (mg/dL) | 29.4 ± 5.5 | 23.5 ± 5.5
Female
Hematology
n | 23 | 24
Erythrocytes (10^6^/mm^3^) | 9.6 ± 0.1 | 9.4 ± 0.1
Hemoglobin (g/dL) | 15.8 ± 0.2 | 16.0 ± 0.1
Hematocrit (%) | 46.1 ± 0.9 | 47.4 ± 0.5
Mean cell volume (fL) | 47.8 ± 0.3 | 50.6 ± 0.2^**^
Mean cell hemoglobin (pg) | 16.5 ± 0.2 | 17.1 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 34.5 ± 0.4 | 33.8 ± 0.2
Leukocytes (10^3^/mm^3^) | 4.7 ± 0.4 | 3.9 ± 0.3
Neutrophils (%) | 5.1 ± 0.3 | 5.2 ± 0.6
Lymphocytes (%) | 87.0 ± 0.9 | 86.7 ± 1.2
Monocytes (%) | 6.4 ± 0.5 | 6.1 ± 0.7
Eosinophils (%) | 0.4 ± 0.1 | 0.5 ± 0.1
Basophils (%) | 1.1 ± 0.2 | 1.5 ± 0.3
Platelets (10^3^/mm^3^) | 732.1 ± 40.1 | 799.3 ± 32.4
Clinical Chemistry
n | 24 | 24
Creatinine (mg/dL) | 0.5 ± 0.0 | 0.5 ± 0.0
Blood urea nitrogen (mg/dL) | 14.7 ± 0.5 | 15.0 ± 0.5

* Significantly different (P≤0.05) from the 0/0/0 mg/kg group by a t-test

** P≤0.01

a Data are presented as mean ± standard error.

TABLE C2 Hematology Data for Heterozygous F1 p53^+/−^ Mice at 160 Days in the 30- and 45-Week In Utero/Postnatal Gavage Studies of AZT^a^

| 0/0/0 mg/kg | 240/120/240 mg/kg
n | 8 | 16
Male
Erythrocytes (10^6^/mm^3^) | 11.2 ± 0.1 | 10.3 ± 0.1^**^
Hemoglobin (g/dL) | 18.4 ± 0.2 | 17.9 ± 0.2^*^
Hematocrit (%) | 55.1 ± 0.7 | 53.5 ± 0.4
Mean cell volume (fL) | 49.1 ± 0.2 | 52.1 ± 0.3^**^
Mean cell hemoglobin (pg) | 16.4 ± 0.1 | 17.4 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 33.5 ± 0.1 | 33.4 ± 0.1
Erythrocyte distribution width (%) | 13.6 ± 0.1 | 13.9 ± 0.1^*^
Female
Erythrocytes (10^6^/mm^3^) | 11.4 ± 0.1 | 10.3 ± 0.2^**^
Hemoglobin (g/dL) | 19.1 ± 0.2 | 17.9 ± 0.4^**^
Hematocrit (%) | 56.6 ± 0.6 | 53.6 ± 1.0^*^
Mean cell volume (fL) | 49.5 ± 0.2 | 52.1 ± 0.2^**^
Mean cell hemoglobin (pg) | 16.7 ± 0.1 | 17.4 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 33.8 ± 0.2 | 33.4 ± 0.1^*^
Erythrocyte distribution width (%) | 13.4 ± 0.1 | 13.6 ± 0.1

* Significantly different (P≤0.05) from the 0/0/0 mg/kg group by a t-test

** P≤0.01

a Data are presented as mean ± standard error. Hematology was performed on subsets of the 160-day-old mice receiving 0/0/0 mg/kg or 240/120/240 mg/kg in order to monitor for macrocytic anemia. Mice from both the 30-week and 45-week studies were evaluated. This evaluation was performed because previous studies (Ayers et al., 1996a) had reported that mice exposed to AZT doses greater than 40 mg/kg per day developed macrocytic anemia severe enough to necessitate reduction of the dose concentration.