# APPENDIX B GENETIC TOXICOLOGY

TABLE B1 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in 1-Day-Old Heterozygous F1 p53^+/−^ Mouse Pups in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| % Reticulocytes | % Micronucleated NCE | % Micronucleated RET
Male
0 mg/kg^b^ | 7 | 7 | 7
Mean ± standard error | 19.9 ± 2.6 | 0.16 ± 0.03 | 0.29 ± 0.04
P value^c^ | P=0.007N | P<0.0001 | P<0.0001
80 mg/kg | 7 | 7 | 7
Mean ± standard error | 14.4 ± 1.3 | 0.81 ± 0.13 | 1.44 ± 0.36
P value | [P=0.189] | [P=0.094] | [P=0.228]
160 mg/kg | 7 | 7 | 7
Mean ± standard error | 12.0 ± 1.2 | 1.26 ± 0.22 | 3.61 ± 0.60
P value | P=0.039N | P=0.0064 | P=0.0016
240 mg/kg | 9 | 9 | 9
Mean ± standard error | 11.8 ± 2.5 | 2.20 ± 0.35 | 4.84 ± 0.87
P value | P=0.024N | P<0.0001 | P<0.0001
Female
0 mg/kg | 6 | 6 | 6
Mean ± standard error | 19.7 ± 1.6 | 0.13 ± 0.04 | 0.27 ± 0.07
P value | P<0.001N | P=0.0006 | P=0.0003
80 mg/kg | 9 | 9 | 9
Mean ± standard error | 11.9 ± 1.1 | 0.96 ± 0.13 | 1.69 ± 0.22
P value | P=0.002N | [P=0.298] | [P=0.314]
160 mg/kg | 12 | 12 | 12
Mean ± standard error | 11.0 ± 1.0 | 1.28 ± 0.16 | 3.27 ± 0.49
P value | P<0.001N | [P=0.152] | P=0.044
240 mg/kg | 9 | 9 | 9
Mean ± standard error | 10.1 ± 1.6 | 3.27 ± 1.00 | 5.82 ± 1.71
P value | P<0.001N | P=0.0007 | P=0.0008

a Dams were dosed from gestational day (GD) 12 through GD 18 with the listed doses; NCE = normochromatic erythrocytes; RET = reticulocytes

b Number examined

c Beneath the 0 mg/kg group percentage is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that exposed group. Two-tailed Dunnett’s tests were used for the % reticulocyte values and one-tailed Dunnett’s tests were used for the % micronucleated NCE and % micronucleated RET values. Nonsignificant P values are indicated with brackets.

TABLE B2 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in 10-Day-Old Heterozygous F1 p53^+/−^ Mouse Pups in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| % Reticulocytes | % Micronucleated NCE | % Micronucleated RET
Male
0/0 mg/kg^b^ | 5 | 5 | 5
Mean ± standard error | 14.1 ± 0.5 | 0.32 ± 0.05 | 0.31 ± 0.05
P value^c^ | [P=0.099] | P<0.0001 | P<0.0001
80/40 mg/kg | 6 | 6 | 6
Mean ± standard error | 17.0 ± 1.4 | 7.23 ± 0.66 | 2.89 ± 0.27
P value | [P=0.55] | P<0.0001 | P=0.0014
160/80 mg/kg | 11 | 11 | 11
Mean ± standard error | 18.8 ± 1.2 | 10.33 ± 0.63 | 7.04 ± 0.42
P value | [P=0.14] | P<0.0001 | P<0.0001
240/120 mg/kg | 8 | 8 | 8
Mean ± standard error | 18.0 ± 2.3 | 4.94 ± 0.62 | 3.34 ± 0.48
P value | [P=0.28] | P<0.0001 | P =0.0001
Female
0/0 mg/kg | 6 | 3 | 3
Mean ± standard error | 19.2 ± 4.0 | 0.27 ± 0.07 | 0.29 ± 0.75
P value | [P=0.29] | P<0.0001 | P=0.0030
80/40 mg/kg | 6 | 9 | 6
Mean ± standard error | 18.0 ± 0.9 | 7.14 ± 0.38 | 2.68 ± 0.29
P value | [P=0.98] | P<0.0001 | [P=0.21]
160/80 mg/kg | 13 | 13 | 13
Mean ± standard error | 22.2 ± 1.8 | 9.85 ± 0.56 | 7.96 ± 0.87
P value | [P=0.79] | P<0.0001 | P=0.0002
240/120 mg/kg | 6 | 6 | 6
Mean ± standard error | 23.2 ± 4.1 | 6.56 ± 1.11 | 5.04 ± 1.36
P value | [P=0.68] | P=0.0002 | P=0.0230

a Pups which had been exposed transplacentally as for Table B1 were dosed with AZT at half the adult dose from postnatal day (PND) 1 until evaluation on PND 10; NCE = normochromatic erythrocytes; RET = reticulocytes

b Number examined

c Beneath the 0/0 mg/kg group percentage is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. Two-tailed Dunnett’s tests were used for the % reticulocyte values and one-tailed Dunnett’s tests were used for the % micronucleated NCE and % micronucleated RET values. Nonsignificant P values are indicated with brackets.

TABLE B3 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in 28-Day-Old Heterozygous F1 p53^+/−^ Mouse Pups in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| % Reticulocytes | % Micronucleated NCE | % Micronucleated RET
Male
0/0/0 mg/kg^b^ | 8 | 8 | 8
Mean ± standard error | 8.03 ± 0.41 | 0.16 ± 0.02 | 0.22 ± 004
P value^c^ | [P=0.19] | P<0.0001 | P<0.0001
80/40/80 mg/kg | 9 | 9 | 9
Mean ± standard error | 6.90 ± 0.33 | 1.76 ± 0.07 | 0.98 ± 0.05
P value | [P=0.08] | P<0.0001 | P<0.0001
160/80/160 mg/kg | 14 | 14 | 14
Mean ± standard error | 7.48 ± 0.28 | 2.70 ± 0.14 | 1.57 ± 0.11
P value | [P=0.34] | P<0.0001 | P<0.0001
240/120/240 mg/kg | 9 | 9 | 9
Mean ± standard error | 7.17 ± 0.34 | 3.22 ± 0.33 | 1.49 ± 0.13
P value | [P=0.22] | P<0.0001 | P<0.0001
Female
0/0/0 mg/kg | 9 | 9 | 9
Mean ± standard error | 6.46 ± 0.90 | 0.13 ± 0.01 | 0.18 ± 0.03
P value | [P=0.20] | P<0.0001 | P<0.0001
80/40/80 mg/kg | 9 | 9 | 9
Mean ± standard error | 6.55 ± 0.66 | 1.63 ± 0.09 | 0.95 ± 0.18
P value | [P=1.00] | [P=0.16] | P=0.0030
160/80/160 mg/kg | 13 | 13 | 13
Mean ± standard error | 6.86 ± 0.51 | 2.50 ± 0.08 | 1.40 ± 0.11
P value | [P=0.99] | P=0.0184 | P<0.0001
240/120/240 mg/kg | 9 | 9 | 9
Mean ± standard error | 8.98 ± 2.51 | 4.62 ± 1.49 | 1.39 ± 0.25
P value | [P=0.42] | P=0.0001 | P<0.0001

a Pups which had been dosed as for Table B2 were dosed with the full dose of AZT from postnatal day (PND) 11 until evaluation on PND 28; NCE = normochromatic erythrocytes; RET = reticulocytes

b Number examined

c Beneath the 0/0/0 mg/kg group percentage is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. Two-tailed Dunnett’s tests were used for the % reticulocyte values and one-tailed Dunnett’s tests were used for the % micronucleated NCE and % micronucleated RET values. Nonsignificant P values are indicated with brackets.

TABLE B4 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in 30-Week-Old Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| % Reticulocytes | % Micronucleated NCE | % Micronucleated RET
Male
0/0/0 mg/kg^b^ | 13 | 13 | 13
Mean ± standard error | 1.67 ± 0.14 | 0.41 ± 0.12 | 0.58 ± 0.12
240/120/240 mg/kg | 13 | 13 | 13
Mean ± standard error | 1.75 ± 0.19 | 1.10 ± 0.17 | 2.28 ± 0.61
P value^c^ | [P=0.74] | P=0.0029 | P=0.0166
Female
0/0/0 mg/kg | 13 | 13 | 13
Mean ± standard error | 1.86 ± 0.23 | 0.44 ± 0.21 | 0.51 ± 0.13
240/120/240 mg/kg | 10 | 10 | 10
Mean ± standard error | 1.93 ± 0.65 | 1.31 ± 0.16 | 2.48 ± 0.19
P value^c^ | [P=0.91] | P=0.0037 | P<0.0001

a Blood samples were taken from mice from the 30-week study at terminal kill; NCE = normochromatic erythrocytes; RET = reticulocytes

b Number examined

c Beneath the dosed group incidences are the P values corresponding to pairwise comparison between the 0/0/0 mg/kg group and the dosed group using a two-tailed Student=s t-test. Nonsignificant P values are indicated with brackets.