# APPENDIX A SUMMARY OF LESIONS IN HETEROZYGOUS F1 p53^+/−^ MICE IN THE IN UTERO/POSTNATAL GAVAGE STUDIES OF AZT

TABLE A1 Summary of the Incidence of Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 27 | 26
Early deaths
Moribund | | 3
Survivors
Died last week of study | | 2
Terminal kill | 27 | 21
Animals examined microscopically | 27 | 26
Alimentary System
Gallbladder | (26) | (26)
Intestine large, cecum | (27) | (26)
Intestine small, jejunum | (27) | (26)
Liver | (27) | (26)
Hepatocellular adenoma | 1 (4%) | 1 (4%)
Pancreas | (27) | (26)
Salivary glands | (27) | (26)
Stomach, glandular | (27) | (26)
Cardiovascular System
Blood vessel | (26) | (25)
Heart | (27) | (26)
Endocrine System
Adrenal cortex | (27) | (26)
Thyroid gland | (26) | (26)
General Body System
None
Genital System
Epididymis | (27) | (26)
Preputial gland | (27) | (26)
Prostate | (27) | (26)
Seminal vesicle | (27) | (26)
Testes | (27) | (26)
Hematopoietic System
Bone marrow | (27) | (26)
Lymph node | (0) | (1)
Lymph node, mandibular | (26) | (26)
Lymph node, mesenteric | (27) | (25)
Spleen | (27) | (26)
Thymus | (26) | (26)
Integumentary System
None
Musculoskeletal System
Bone, femur | (27) | (26)
Osteosarcoma | | 1 (4%)
Nervous System
Brain, brain stem | (27) | (26)
Astrocytoma malignant, metastatic, brain, cerebrum | | 1 (4%)
Brain, cerebellum | (27) | (26)
Astrocytoma malignant, metastatic, brain, cerebrum | | 1 (4%)
Brain, cerebrum | (27) | (26)
Astrocytoma malignant | | 1 (4%)
Olfactory lobe, neuroblastoma | | 1 (4%)
Respiratory System
Lung | (27) | (26)
Nose | (27) | (26)
Neuroblastoma, metastatic, brain, cerebrum | | 1 (4%)
Special Senses System
Eye | (27) | (26)
Harderian gland | (27) | (26)
Urinary System
Kidney | (27) | (26)
Urinary bladder | (27) | (26)
Systemic Lesions
Multiple organs^b^ | (27) | (26)
Lymphoma malignant | | 3 (12%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 7
Total primary neoplasms | 1 | 7
Total animals with benign neoplasms | 1 | 1
Total benign neoplasms | 1 | 1
Total animals with malignant neoplasms | | 6
Total malignant neoplasms | | 6
Total animals with metastatic neoplasms | | 2
Total metastatic neoplasms | | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate^b^ | 3.7% | 4.4%
Terminal rate^c^ | 1/27 (3.7%) | 1/21 (4.8%)
First incidence (days) | 217 (T) | 213 (T)
Poly-3 test^d^ | | P=0.722
All Organs: Malignant Lymphoma
Overall rate | 0/27 (0.0%) | 3/26 (11.5%)
Adjusted rate | 0.0% | 11.9%
Terminal rate | 0/27 (0.0%) | 0/21 (0.0%)
First incidence (days) | —^e^ | 84
Poly-3 test | | P=0.102
All Organs: Osteosarcoma
Overall rate | 0/27 (0.0%) | 1/26 (3.8%)
Adjusted rate | 0.0% | 4.4%
Terminal rate | 0/27 (0.0%) | 1/21 (4.8%)
First incidence (days) | — | 213 (T)
Poly-3 test | | P=0.467
All Organs: Benign Neoplasms
Overall rate | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate | 3.7% | 4.4%
Terminal rate | 1/27 (3.7%) | 1/21 (4.8%)
First incidence (days) | 217 (T) | 213 (T)
Poly-3 test | | P=0.722
All Organs: Malignant Neoplasms
Overall rate | 0/27 (0.0%) | 6/26 (23.1%)
Adjusted rate | 0.0% | 23.8%
Terminal rate | 0/27 (0.0%) | 2/21 (9.5%)
First incidence (days) | — | 84
Poly-3 test | | P=0.008
All Organs: Benign or Malignant Neoplasms
Overall rate | 1/27 (3.7%) | 7/26 (26.9%)
Adjusted rate | 3.7% | 27.8%
Terminal rate | 1/27 (3.7%) | 3/21 (14.3%)
First incidence (days) | 217 (T) | 84
Poly-3 test | | P=0.017

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

e Not applicable; no neoplasms in animal group

TABLE A3 Summary of the Incidence of Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 27 | 26
Early deaths
Moribund | | 3
Survivors
Died last week of study | | 2
Terminal kill | 27 | 21
Animals examined microscopically | 27 | 26
Alimentary System
Gallbladder | (26) | (26)
Intestine large, cecum | (27) | (26)
Hyperplasia, lymphoid | 3 (11%) | 1 (4%)
Intestine small, jejunum | (27) | (26)
Liver | (27) | (26)
Fatty change | | 1 (4%)
Vacuolization cytoplasmic | 8 (30%) | 4 (15%)
Pancreas | (27) | (26)
Salivary glands | (27) | (26)
Infiltration cellular, lymphocyte | 5 (19%)
Stomach, glandular | (27) | (26)
Cardiovascular System
Blood vessel | (26) | (25)
Heart | (27) | (26)
Cardiomyopathy | 2 (7%)
Endocrine System
Adrenal cortex | (27) | (26)
Subcapsular, hyperplasia | 2 (7%) | 2 (8%)
Thyroid gland | (26) | (26)
Cyst | | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%)
General Body System
None
Genital System
Epididymis | (27) | (26)
Preputial gland | (27) | (26)
Atrophy | | 1 (4%)
Prostate | (27) | (26)
Inflammation, suppurative | | 1 (4%)
Seminal vesicle | (27) | (26)
Lumen, dilatation | | 1 (4%)
Testes | (27) | (26)
Seminiferous tubule, degeneration | | 1 (4%)
Hematopoietic System
Bone marrow | (27) | (26)
Myeloid cell, hyperplasia | | 1 (4%)
Lymph node | (0) | (1)
Lymph node, mandibular | (26) | (26)
Hyperplasia, lymphoid | 1 (4%) | 1 (4%)
Lymph node, mesenteric | (27) | (25)
Hyperplasia, lymphoid | 19 (70%) | 16 (64%)
Hyperplasia, plasma cell | 1 (4%)
Spleen | (27) | (26)
Hematopoietic cell proliferation | 1 (4%) | 2 (8%)
Hyperplasia, lymphoid | 2 (7%)
Thymus | (26) | (26)
Atrophy | | 1 (4%)
Hyperplasia, lymphoid | | 2 (8%)
Integumentary System
None
Musculoskeletal System
Bone, femur | (27) | (26)
Nervous System
Brain, brain stem | (27) | (26)
Brain, cerebellum | (27) | (26)
Brain, cerebrum | (27) | (26)
Respiratory System
Lung | (27) | (26)
Abscess | | 1 (4%)
Nose | (27) | (26)
Inflammation, suppurative | 1 (4%) | 1 (4%)
Special Senses System
Eye | (27) | (26)
Harderian gland | (27) | (26)
Epithelium, hyperplasia | | 1 (4%)
Urinary System
Kidney | (27) | (26)
Bacterium | | 1 (4%)
Infiltration cellular, lymphocyte | 7 (26%) | 2 (8%)
Inflammation, chronic active | | 1 (4%)
Nephropathy | | 1 (4%)
Pelvis, dilatation | | 2 (8%)
Transitional epithelium, hyperplasia | 1 (4%) | 1 (4%)
Urinary bladder | (27) | (26)
Lumen, dilatation | 1 (4%) | 2 (8%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A4 Summary of the Incidence of Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 27 | 26
Early deaths
Moribund | 1
Natural death | 1
Survivors
Died last week of study | 1
Terminal kill | 24 | 26
Animals examined microscopically | 27 | 26
Alimentary System
Esophagus | (23) | (25)
Gallbladder | (24) | (25)
Sarcoma | | 1 (4%)
Intestine large, cecum | (26) | (26)
Polyp | 1 (4%)
Intestine large, rectum | (26) | (26)
Intestine small, ileum | (26) | (26)
Liver | (26) | (26)
Sarcoma | | 1 (4%)
Pancreas | (26) | (26)
Salivary glands | (26) | (26)
Stomach, glandular | (26) | (26)
Cardiovascular System
Heart | (26) | (26)
Endocrine System
Adrenal cortex | (26) | (26)
Adrenal medulla | (26) | (26)
Parathyroid gland | (22) | (21)
Pituitary gland | (26) | (26)
Thyroid gland | (26) | (25)
General Body System
Tissue NOS | (0) | (1)
Genital System
Ovary | (26) | (26)
Uterus | (26) | (26)
Endometrium, polyp stromal | 1 (4%)
Vagina | (27) | (26)
Hematopoietic System
Bone marrow | (26) | (26)
Lymph node | (3) | (1)
Lymph node, mandibular | (26) | (25)
Lymph node, mesenteric | (24) | (25)
Sarcoma, metastatic, liver | | 1 (4%)
Spleen | (26) | (26)
Sarcoma, metastatic, liver | | 1 (4%)
Thymus | (26) | (26)
Integumentary System
Mammary gland | (24) | (24)
Adenocarcinoma | 1 (4%)
Skin | (26) | (26)
Basal cell carcinoma | | 1 (4%)
Musculoskeletal System
None
Nervous System
Brain, cerebrum | (26) | (26)
Respiratory System
Lung | (26) | (26)
Adenocarcinoma, metastatic, mammary gland | 1 (4%)
Basal cell carcinoma, metastatic, skin | | 1 (4%)
Special Senses System
Harderian gland | (26) | (26)
Urinary System
Kidney | (26) | (26)
Urinary bladder | (26) | (26)
Systemic Lesions
Multiple organs^b^ | (27) | (26)
Lymphoma malignant | 1 (4%) | 1 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 4 | 3
Total primary neoplasms | 4 | 4
Total animals with benign neoplasms | 2
Total benign neoplasms | 2
Total animals with malignant neoplasms | 2 | 3
Total malignant neoplasms | 2 | 4
Total animals with metastatic neoplasms | 1 | 2
Total metastatic neoplasms | 1 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A5 Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
All Organs: Malignant Lymphoma
Overall rate^a^ | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate^b^ | 4.0% | 3.8%
Terminal rate^c^ | 0/24 (0.0%) | 1/26 (3.8%)
First incidence (days) | 192 | 213 (T)
Poly-3 test^d^ | | P=0.753N
All Organs: Benign Neoplasms
Overall rate | 2/27 (7.4%) | 0/26 (0.0%)
Adjusted rate | 8.0% | 0.0%
Terminal rate | 2/24 (8.3%) | 0/26 (0.0%)
First incidence (days) | 211 (T) | —^e^
Poly-3 test | | P=0.225N
All Organs: Malignant Neoplasms
Overall rate | 2/27 (7.4%) | 3/26 (11.5%)
Adjusted rate | 7.9% | 11.5%
Terminal rate | 1/24 (4.2%) | 3/26 (11.5%)
First incidence (days) | 192 | 213 (T)
Poly-3 test | | P=0.515
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/27 (14.8%) | 3/26 (11.5%)
Adjusted rate | 15.9% | 11.5%
Terminal rate | 3/24 (12.5%) | 3/26 (11.5%)
First incidence (days) | 192 | 213 (T)
Poly-3 test | | P=0.482N

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals examined microscopically.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE A6 Summary of the Incidence of Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 27 | 26
Early deaths
Moribund kill | 1
Natural death | 1
Survivors
Died last week of study | 1
Terminal kill | 24 | 26
Animals examined microscopically | 27 | 26
Alimentary System
Esophagus | (23) | (25)
Adventitia, foreign body | 1 (4%)
Adventitia, necrosis | 1 (4%)
Gallbladder | (24) | (25)
Intestine large, cecum | (26) | (26)
Hyperplasia, lymphoid | | 2 (8%)
Intestine large, rectum | (26) | (26)
Intestine small, ileum | (26) | (26)
Liver | (26) | (26)
Infiltration cellular, lymphocyte | | 1 (4%)
Inflammation, chronic active | 3 (12%) | 2 (8%)
Tension lipidosis | 1 (4%) | 3 (12%)
Vacuolization cytoplasmic | 1 (4%) | 1 (4%)
Pancreas | (26) | (26)
Infiltration cellular, lymphocyte | | 1 (4%)
Inflammation, chronic active | | 1 (4%)
Salivary glands | (26) | (26)
Infiltration cellular, lymphocyte | 14 (54%) | 7 (27%)
Stomach, glandular | (26) | (26)
Cardiovascular System
Heart | (26) | (26)
Cardiomyopathy | 1 (4%)
Pericardium, inflammation, chronic | 1 (4%)
Pericardium, inflammation, chronic active | | 1 (4%)
Pericardium, mineralization | | 1 (4%)
Endocrine System
Adrenal cortex | (26) | (26)
Accessory adrenal cortical nodule | 1 (4%) | 1 (4%)
Vacuolization cytoplasmic | 2 (8%)
Subcapsular, hyperplasia | 23 (88%) | 24 (92%)
Adrenal medulla | (26) | (26)
Parathyroid gland | (22) | (21)
Infiltration cellular, lymphocyte | 1 (5%)
Pituitary gland | (26) | (26)
Thyroid gland | (26) | (25)
Cyst | 1 (4%)
Infiltration cellular, lymphocyte | 1 (4%) | 1 (4%)
General Body System
Tissue NOS | (0) | (1)
Abscess | | 1 (100%)
Genital System
Ovary | (26) | (26)
Cyst | | 1 (4%)
Uterus | (26) | (26)
Endometrium, hyperplasia, cystic | 1 (4%) | 1 (4%)
Lumen, dilatation | 2 (8%) | 2 (8%)
Vagina | (27) | (26)
Hematopoietic System
Bone marrow | (26) | (26)
Myeloid cell, hyperplasia | 3 (12%) | 2 (8%)
Lymph node | (3) | (1)
Mediastinal, hyperplasia, lymphoid | 2 (67%)
Mediastinal, infiltration cellular, plasma cell | 1 (33%)
Lymph node, mandibular | (26) | (25)
Hyperplasia, lymphoid | 3 (12%) | 2 (8%)
Lymph node, mesenteric | (24) | (25)
Hyperplasia, lymphoid | 7 (29%) | 11 (44%)
Spleen | (26) | (26)
Depletion lymphoid | 1 (4%)
Hematopoietic cell proliferation | 3 (12%) | 2 (8%)
Hyperplasia, lymphoid | | 2 (8%)
Thymus | (26) | (26)
Hyperplasia, lymphoid | 3 (12%) | 2 (8%)
Hyperplasia, plasma cell | 1 (4%)
Necrosis | 1 (4%)
Adventitia, inflammation, chronic | 1 (4%)
Epithelial cell, hyperplasia | 1 (4%)
Integumentary System
Mammary gland | (24) | (24)
Skin | (26) | (26)
Musculoskeletal System
None
Nervous System
Brain, cerebrum | (26) | (26)
Cyst epithelial inclusion | 1 (4%)
Respiratory System
Lung | (26) | (26)
Abscess | 2 (8%)
Infiltration cellular, lymphocyte | 1 (4%)
Inflammation, chronic active | | 1 (4%)
Mediastinum, inflammation, chronic active | | 1 (4%)
Mediastinum, mineralization | | 1 (4%)
Mediastinum, necrosis | 1 (4%)
Special Senses System
Harderian gland | (26) | (26)
Infiltration cellular, lymphocyte | 1 (4%)
Urinary System
Kidney | (26) | (26)
Infiltration cellular, lymphocyte | 8 (31%) | 3 (12%)
Inflammation, chronic active | 1 (4%)
Urinary bladder | (26) | (26)
Infiltration cellular, lymphocyte | 3 (12%) | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A7 Summary of the Incidence of Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 27 | 27 | 27 | 27
Early deaths
Moribund | 1 | 1 | | 1
Natural death | 1 | 2 | | 1
Survivors
Died last week of study | 1 | 3 | | 3
Terminal kill | 24 | 21 | 27 | 22
Animals examined microscopically | 27 | 27 | 27 | 27
Alimentary System
Esophagus | (27) | (26) | (27) | (27)
Gallbladder | (26) | (25) | (27) | (25)
Intestine large, cecum | (26) | (26) | (27) | (25)
Intestine large, colon | (26) | (26) | (27) | (25)
Intestine large, rectum | (26) | (26) | (27) | (26)
Intestine small, duodenum | (26) | (25) | (27) | (25)
Liver | (26) | (27) | (27) | (27)
Hepatocellular adenoma | 3 (12%) | 2 (7%) | 6 (22%) | 9 (33%)
Hepatocellular carcinoma | | 1 (4%)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Mesentery | (0) | (2) | (1) | (0)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (50%)
Pancreas | (27) | (27) | (27) | (27)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Salivary glands | (27) | (26) | (27) | (27)
Stomach, forestomach | (26) | (26) | (27) | (27)
Squamous cell carcinoma | | 1 (4%)
Stomach, glandular | (26) | (26) | (27) | (25)
Adenocarcinoma | | 1 (4%)
Cardiovascular System
Blood vessel | (27) | (27) | (27) | (27)
Heart | (27) | (27) | (27) | (27)
Endocrine System
Adrenal cortex | (27) | (27) | (27) | (27)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Adrenal medulla | (25) | (26) | (24) | (26)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Islets, pancreatic | (27) | (27) | (27) | (27)
Parathyroid gland | (16) | (20) | (21) | (22)
Pituitary gland | (25) | (27) | (27) | (27)
Thyroid gland | (26) | (27) | (27) | (26)
General Body System
Tissue NOS | (2) | (1) | (0) | (1)
Sarcoma | 1 (50%)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (100%)
Genital System
Coagulating gland | (0) | (1) | (0) | (0)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (100%)
Epididymis | (27) | (27) | (27) | (26)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Preputial gland | (27) | (26) | (27) | (26)
Prostate | (27) | (27) | (27) | (25)
Seminal vesicle | (26) | (27) | (27) | (26)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Testes | (27) | (26) | (27) | (26)
Hematopoietic System
Bone marrow | (27) | (26) | (27) | (26)
Lymph node | (0) | (1) | (0) | (1)
Lymph node, mandibular | (27) | (25) | (27) | (26)
Lymph node, mesenteric | (26) | (23) | (26) | (25)
Spleen | (26) | (25) | (27) | (25)
Thymus | (27) | (24) | (27) | (24)
Squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Integumentary System
Skin | (27) | (27) | (27) | (27)
Subcutaneous tissue, fibrosarcoma | | | | 1 (4%)
Musculoskeletal System
Bone | (1) | (0) | (0) | (0)
Humerus, osteosarcoma | 1 (100%)
Bone, femur | (27) | (27) | (27) | (27)
Osteosarcoma | 1 (4%)
Skeletal muscle | (27) | (27) | (27) | (27)
Diaphragm, squamous cell carcinoma, metastatic, stomach, forestomach | | 1 (4%)
Nervous System
Brain, cerebellum | (27) | (27) | (27) | (27)
Brain, cerebrum | (27) | (27) | (27) | (27)
Olfactory lobe, neuroblastoma | | 1 (4%) | | 1 (4%)
Respiratory System
Lung | (27) | (27) | (27) | (27)
Alveolar/bronchiolar carcinoma | | 1 (4%)
Osteosarcoma, metastatic, bone, femur | 1 (4%)
Nose | (27) | (27) | (27) | (25)
Neuroblastoma, metastatic, brain, cerebrum | | 1 (4%) | | 1 (4%)
Special Senses System
Harderian gland | (27) | (27) | (27) | (27)
Adenoma | 1 (4%)
Urinary System
Kidney | (26) | (27) | (27) | (26)
Urinary bladder | (27) | (27) | (27) | (26)
Systemic Lesions
Multiple organs^b^ | (27) | (27) | (27) | (27)
Lymphoma malignant | 1 (4%) | 2 (7%) | 1 (4%) | 1 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 8 | 7 | 7 | 12
Total primary neoplasms | 8 | 9 | 7 | 12
Total animals with benign neoplasms | 4 | 2 | 6 | 9
Total benign neoplasms | 4 | 2 | 6 | 9
Total animals with malignant neoplasms | 4 | 6 | 1 | 3
Total malignant neoplasms | 4 | 7 | 1 | 3
Total animals with metastatic neoplasms | 1 | 2 | | 1
Total metastatic neoplasms | 1 | 12 | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A8 Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 3/26 (11.5%) | 2/27 (7.4%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate^b^ | 12.3% | 8.8% | 22.2% | 36.5%
Terminal rate^c^ | 3/24 (12.5%) | 2/21 (9.5%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test^d^ | P=0.013 | P=0.531N | P=0.288 | P=0.048
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/26 (11.5%) | 3/27 (11.1%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate | 12.3% | 13.2% | 22.2% | 36.5%
Terminal rate | 3/24 (12.5%) | 3/21 (14.3%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test | P=0.019 | P=0.634 | P=0.288 | P=0.048
All Organs: Malignant Lymphoma
Overall rate | 1/27 (3.7%) | 2/27 (7.4%) | 1/27 (3.7%) | 1/27 (3.7%)
Adjusted rate | 3.9% | 8.5% | 3.7% | 4.1%
Terminal rate | 0/24 (0.0%) | 1/21 (4.8%) | 1/27 (3.7%) | 0/22 (0.0%)
First incidence (days) | 159 | 217 | 321 (T) | 94
Poly-3 test | P=0.502N | P=0.473 | P=0.746N | P=0.754
All Organs: Osteosarcoma
Overall rate | 2/27 (7.4%) | 0/27 (0.0%) | 0/27 (0.0%) | 0/27 (0.0%)
Adjusted rate | 8.2% | 0.0% | 0.0% | 0.0%
Terminal rate | 2/24 (8.3%) | 0/21 (0.0%) | 0/27 (0.0%) | 0/22 (0.0%)
First incidence (days) | 319 (T) | —^e^ | — | —
Poly-3 test | P=0.050N | P=0.251N | P=0.214N | P=0.242N
All Organs: Benign Neoplasms
Overall rate | 4/27 (14.8%) | 2/27 (7.4%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate | 16.3% | 8.8% | 22.2% | 36.5%
Terminal rate | 4/24 (16.7%) | 2/21 (9.5%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test | P=0.031 | P=0.367N | P=0.430 | P=0.099
All Organs: Malignant Neoplasms
Overall rate | 4/27 (14.8%) | 6/27 (22.2%) | 1/27 (3.7%) | 3/27 (11.1%)
Adjusted rate | 15.8% | 25.0% | 3.7% | 12.2%
Terminal rate | 3/24 (12.5%) | 3/21 (14.3%) | 1/27 (3.7%) | 2/22 (9.1%)
First incidence (days) | 159 | 217 | 321 (T) | 94
Poly-3 test | P=0.176N | P=0.328 | P=0.155N | P=0.516N
All Organs: Benign or Malignant Neoplasms
Overall rate | 8/27 (29.6%) | 7/27 (25.9%) | 7/27 (25.9%) | 12/27 (44.4%)
Adjusted rate | 31.5% | 29.1% | 25.9% | 46.8%
Terminal rate | 7/24 (29.2%) | 4/21 (19.0%) | 7/27 (25.9%) | 9/22 (40.9%)
First incidence (days) | 159 | 217 | 320 (T) | 94
Poly-3 test | P=0.185 | P=0.550N | P=0.444N | P=0.205

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE A9 Summary of the Incidence of Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 27 | 27 | 27 | 27
Early deaths
Moribund | 1 | 1 | | 1
Natural death | 1 | 2 | | 1
Survivors
Died last week of study | 1 | 3 | | 3
Terminal kill | 24 | 21 | 27 | 22
Animals examined microscopically | 27 | 27 | 27 | 27
Alimentary System
Esophagus | (27) | (26) | (27) | (27)
Foreign body | | 1 (4%)
Adventitia, inflammation, suppurative | | 1 (4%)
Adventitia, necrosis | | 1 (4%)
Gallbladder | (26) | (25) | (27) | (25)
Mineralization | | | | 1 (4%)
Intestine large, cecum | (26) | (26) | (27) | (25)
Hyperplasia, lymphoid | | 2 (8%) | 2 (7%) | 3 (12%)
Intestine large, colon | (26) | (26) | (27) | (25)
Epithelium, hyperplasia | | | | 1 (4%)
Intestine large, rectum | (26) | (26) | (27) | (26)
Hyperplasia, lymphoid | | | | 1 (4%)
Intestine small, duodenum | (26) | (25) | (27) | (25)
Inflammation, chronic active | | | 1 (4%)
Liver | (26) | (27) | (27) | (27)
Basophilic focus | 1 (4%) | 1 (4%) | | 1 (4%)
Cytomegaly | 14 (54%) | 14 (52%) | 13 (48%) | 9 (33%)
Hematopoietic cell proliferation | 1 (4%)
Mixed cell focus | | | | 1 (4%)
Tension lipidosis | 3 (12%) | | | 1 (4%)
Vacuolization cytoplasmic | 20 (77%) | 17 (63%) | 23 (85%) | 13 (48%)
Mesentery | (0) | (2) | (1) | (0)
Fat, fibrosis | | | 1 (100%)
Pancreas | (27) | (27) | (27) | (27)
Cytoplasmic alteration | | | 1 (4%)
Inflammation, chronic active | | | 1 (4%) | 1 (4%)
Pigmentation | | | 1 (4%)
Acinar cell, degeneration | 1 (4%)
Salivary glands | (27) | (26) | (27) | (27)
Infiltration cellular, lymphocyte | 7 (26%) | 4 (15%) | 2 (7%) | 5 (19%)
Stomach, forestomach | (26) | (26) | (27) | (27)
Epithelium, hyperplasia | 1 (4%)
Epithelium, hyperplasia, squamous | | 1 (4%)
Stomach, glandular | (26) | (26) | (27) | (25)
Cardiovascular System
Blood vessel | (27) | (27) | (27) | (27)
Heart | (27) | (27) | (27) | (27)
Inflammation, suppurative | | 1 (4%)
Polyarteritis | | | 1 (4%)
Pericardium, inflammation, chronic active | 1 (4%)
Endocrine System
Adrenal cortex | (27) | (27) | (27) | (27)
Accessory adrenal cortical nodule | 1 (4%)
Cyst | 1 (4%)
Hypertrophy | 1 (4%) | | 1 (4%)
Subcapsular, hyperplasia | 6 (22%) | 6 (22%) | 7 (26%) | 6 (22%)
Adrenal medulla | (25) | (26) | (24) | (26)
Islets, pancreatic | (27) | (27) | (27) | (27)
Hyperplasia | | | 1 (4%)
Parathyroid gland | (16) | (20) | (21) | (22)
Cyst | | | | 1 (5%)
Pituitary gland | (25) | (27) | (27) | (27)
Thyroid gland | (26) | (27) | (27) | (26)
Cyst | 1 (4%) | 1 (4%)
Degeneration | | 1 (4%)
Ectopic thymus | | 1 (4%)
Follicular cell, hyperplasia | | | 1 (4%)
General Body System
Tissue NOS | (2) | (1) | (0) | (1)
Mediastinum, abscess | 1 (50%)
Thoracic, thrombosis | | | | 1 (100%)
Genital System
Coagulating gland | (0) | (1) | (0) | (0)
Epididymis | (27) | (27) | (27) | (26)
Hypospermia | | 1 (4%) | | 1 (4%)
Preputial gland | (27) | (26) | (27) | (26)
Degeneration | | | | 3 (12%)
Infiltration cellular, lymphocyte | 1 (4%)
Inflammation, suppurative | | 1 (4%)
Inflammation, chronic active | | | | 1 (4%)
Duct, dilatation | | 1 (4%)
Prostate | (27) | (27) | (27) | (25)
Seminal vesicle | (26) | (27) | (27) | (26)
Inflammation, chronic | | | | 1 (4%)
Testes | (27) | (26) | (27) | (26)
Interstitial cell, hyperplasia | | 1 (4%)
Seminiferous tubule, degeneration | | 1 (4%) | 1 (4%) | 1 (4%)
Hematopoietic System
Bone marrow | (27) | (26) | (27) | (26)
Myeloid cell, hyperplasia | 2 (7%) | 2 (8%) | 1 (4%)
Lymph node | (0) | (1) | (0) | (1)
Lymph node, mandibular | (27) | (25) | (27) | (26)
Hyperplasia, lymphoid | 1 (4%) | 1 (4%) | 1 (4%) | 2 (8%)
Hyperplasia, plasma cell | | | 1 (4%)
Lymph node, mesenteric | (26) | (23) | (26) | (25)
Hematopoietic cell proliferation | | | | 1 (4%)
Hyperplasia, lymphoid | 13 (50%) | 12 (52%) | 17 (65%) | 14 (56%)
Hyperplasia, plasma cell | | | 1 (4%)
Infiltration cellular, histiocyte | | | 1 (4%)
Infiltration cellular, polymorphonuclear | | | | 1 (4%)
Spleen | (26) | (25) | (27) | (25)
Hematopoietic cell proliferation | 4 (15%) | 2 (8%) | 5 (19%) | 1 (4%)
Hemorrhage | | | | 1 (4%)
Hyperplasia, lymphoid | 2 (8%) | 5 (20%) | 6 (22%) | 2 (8%)
Thymus | (27) | (24) | (27) | (24)
Atrophy | 1 (4%) | | 1 (4%)
Hyperplasia, lymphoid | 1 (4%) | 1 (4%)
Integumentary System
Skin | (27) | (27) | (27) | (27)
Abscess | | | | 1 (4%)
Cyst epithelial inclusion | | | 1 (4%)
Hemorrhage | | | | 1 (4%)
Musculoskeletal System
Bone | (1) | (0) | (0) | (0)
Bone, femur | (27) | (27) | (27) | (27)
Skeletal muscle | (27) | (27) | (27) | (27)
Diaphragm, foreign body | | 1 (4%)
Diaphragm, inflammation, granulomatous | | 1 (4%)
Nervous System
Brain, cerebellum | (27) | (27) | (27) | (27)
Hemorrhage | | | | 1 (4%)
Brain, cerebrum | (27) | (27) | (27) | (27)
Mineralization | 4 (15%) | 1 (4%) | 2 (7%)
Respiratory System
Lung | (27) | (27) | (27) | (27)
Congestion | 1 (4%) | | | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%)
Infiltration cellular, polymorphonuclear | | | | 1 (4%)
Inflammation, chronic active | 1 (4%)
Mediastinum, inflammation, suppurative | | 1 (4%)
Mediastinum, necrosis | | 1 (4%)
Nose | (27) | (27) | (27) | (25)
Exudate | 1 (4%)
Inflammation, suppurative | 1 (4%)
Special Senses System
Harderian gland | (27) | (27) | (27) | (27)
Urinary System
Kidney | (26) | (27) | (27) | (26)
Casts protein | | 1 (4%) | | 1 (4%)
Cyst | 1 (4%) | 1 (4%)
Infiltration cellular, lymphocyte | 6 (23%) | 11 (41%) | 6 (22%) | 4 (15%)
Pelvis, dilatation | | | | 1 (4%)
Pelvis, inflammation, chronic | | | | 1 (4%)
Urinary bladder | (27) | (27) | (27) | (26)
Lumen, dilatation | | 1 (4%) | 2 (7%) | 2 (8%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A10 Summary of the Incidence of Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 26 | 27 | 27 | 27
Early deaths
Moribund | 1 | | | 1
Natural death | | 1 | 1
Survivors
Died last week of study | 2 | 3 | 2 | 5
Terminal kill | 23 | 23 | 24 | 21
Animals examined microscopically | 26 | 27 | 27 | 27
Alimentary System
Esophagus | (26) | (27) | (27) | (27)
Intestine large, cecum | (25) | (27) | (25) | (24)
Intestine large, colon | (26) | (26) | (27) | (25)
Intestine large, rectum | (25) | (27) | (27) | (25)
Intestine small, ileum | (25) | (27) | (25) | (25)
Intestine small, jejunum | (25) | (27) | (25) | (25)
Liver | (26) | (27) | (27) | (27)
Sarcoma | 1 (4%)
Mesentery | (1) | (0) | (1) | (1)
Pancreas | (26) | (27) | (27) | (26)
Salivary glands | (26) | (27) | (26) | (27)
Stomach, forestomach | (26) | (27) | (27) | (27)
Squamous cell papilloma | | 1 (4%)
Cardiovascular System
Heart | (26) | (27) | (27) | (26)
Endocrine System
Adrenal cortex | (26) | (27) | (27) | (26)
Adenoma | | | 1 (4%)
Parathyroid gland | (21) | (22) | (22) | (22)
Pituitary gland | (26) | (27) | (27) | (27)
Thyroid gland | (25) | (27) | (27) | (26)
General Body System
Tissue NOS | (0) | (1) | (0) | (1)
Thoracic, osteosarcoma | | 1 (100%)
Genital System
Clitoral gland | (25) | (26) | (26) | (27)
Ovary | (26) | (27) | (27) | (26)
Luteoma | 1 (4%)
Uterus | (26) | (27) | (27) | (27)
Endometrium, polyp stromal | | 1 (4%)
Vagina | (25) | (27) | (27) | (24)
Hematopoietic System
Bone marrow | (26) | (26) | (26) | (26)
Sarcoma | 1 (4%)
Lymph node | (1) | (1) | (0) | (3)
Lymph node, mandibular | (26) | (27) | (25) | (26)
Sarcoma | 1 (4%)
Lymph node, mesenteric | (26) | (26) | (26) | (27)
Sarcoma | 1 (4%)
Spleen | (26) | (26) | (27) | (27)
Sarcoma | 1 (4%)
Thymus | (24) | (26) | (23) | (27)
Integumentary System
Mammary gland | (25) | (26) | (27) | (27)
Adenocarcinoma | | | 2 (7%) | 1 (4%)
Skin | (26) | (27) | (27) | (27)
Fibrosarcoma | | | | 1 (4%)
Squamous cell carcinoma | | | 1 (4%)
Musculoskeletal System
Bone | (0) | (1) | (0) | (1)
Cranium, osteoma | | | | 1 (100%)
Rib, osteosarcoma | | 1 (100%)
Bone, femur | (26) | (27) | (27) | (27)
Osteosarcoma | 1 (4%) | | 2 (7%) | 1 (4%)
Skeletal muscle | (26) | (27) | (27) | (27)
Nervous System
Brain, brain stem | (26) | (27) | (27) | (27)
Brain, cerebrum | (26) | (27) | (27) | (27)
Sarcoma | 1 (4%)
Peripheral nerve | (2) | (0) | (0) | (0)
Spinal cord | (1) | (0) | (0) | (0)
Respiratory System
Lung | (26) | (27) | (26) | (27)
Alveolar/bronchiolar adenoma | | 1 (4%)
Osteosarcoma, metastatic, bone, femur | | | | 1 (4%)
Mediastinum, sarcoma | 1 (4%)
Nose | (26) | (27) | (27) | (27)
Osteosarcoma | | | 1 (4%)
Sarcoma | 1 (4%)
Special Senses System
Eye | (25) | (25) | (26) | (24)
Harderian gland | (26) | (27) | (27) | (25)
Adenoma | | | 1 (4%)
Urinary System
Kidney | (26) | (27) | (27) | (27)
Renal tubule, adenoma | | 1 (4%)
Ureter | (0) | (0) | (1) | (0)
Urinary bladder | (26) | (27) | (27) | (26)
Systemic Lesions
Multiple organs^b^ | (26) | (27) | (27) | (27)
Histiocytic sarcoma | | 1 (4%) | | 1 (4%)
Lymphoma malignant | | | 1 (4%) | 3 (11%)
Mesothelioma malignant | 1 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 4 | 7 | 8 | 8
Total primary neoplasms | 11 | 7 | 9 | 8
Total animals with benign neoplasms | 1 | 4 | 2 | 1
Total benign neoplasms | 1 | 4 | 2 | 1
Total animals with malignant neoplasms | 3 | 3 | 6 | 7
Total malignant neoplasms | 10 | 3 | 7 | 7
Total animals with metastatic neoplasms | | | | 1
Total metastatic neoplasms | | | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A11 Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
All Organs: Malignant Lymphoma
Overall rate^a^ | 0/26 (0.0%) | 0/27 (0.0%) | 1/27 (3.7%) | 3/27 (11.1%)
Adjusted rate^b^ | 0.0% | 0.0% | 4.0% | 12.2%
Terminal rate^c^ | 0/23 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%) | 2/21 (9.5%)
First incidence (days) | —^e^ | — | 322 (T) | 241
Poly-3 test^d^ | P=0.020 | —^f^ | P=0.505 | P=0.115
All Organs: Histiocytic Sarcoma
Overall rate | 0/26 (0.0%) | 1/27 (3.7%) | 0/27 (0.0%) | 1/27 (3.7%)
Adjusted rate | 0.0% | 3.9% | 0.0% | 4.1%
Terminal rate | 0/23 (0.0%) | 0/23 (0.0%) | 0/24 (0.0%) | 0/21 (0.0%)
First incidence (days) | — | 212 | — | 278
Poly-3 test | P=0.378 | P=0.509 | — | P=0.500
All Organs: Osteosarcoma
Overall rate | 1/26 (3.8%) | 2/27 (7.4%) | 3/27 (11.1%) | 1/27 (3.7%)
Adjusted rate | 4.0% | 7.9% | 12.0% | 4.1%
Terminal rate | 0/23 (0.0%) | 1/23 (4.3%) | 3/24 (12.5%) | 0/21 (0.0%)
First incidence (days) | 269 | 282 | 320 (T) | 287
Poly-3 test | P=0.486 | 0.504 | 0.305 | 0.756
All Organs: Mesothelioma
Overall rate | 1/26 (3.8%) | 0/27 (0.0%) | 0/27 (0.0%) | 0/27 (0.0%)
Adjusted rate | 4.0% | 0.0% | 0.0% | 0.0%
Terminal rate | 0/23 (0.0%) | 0/23 (0.0%) | 0/24 (0.0%) | 0/21 (0.0%)
First incidence (days) | 291 | — | — | —
Poly-3 test | P=0.186N | P=0.499N | P=0.497N | P=0.506N
All Organs: Benign Neoplasms
Overall rate | 1/26 (3.8%) | 4/27 (14.8%) | 2/27 (7.4%) | 1/27 (3.7%)
Adjusted rate | 4.1% | 16.1% | 8.0% | 4.2%
Terminal rate | 1/23 (4.3%) | 4/23 (17.4%) | 2/24 (8.3%) | 1/21 (4.8%)
First incidence (days) | 320 (T) | 319 (T) | 322 (T) | 321 (T)
Poly-3 test | P=0.452N | P=0.177 | P=0.509 | P=0.757
All Organs: Malignant Neoplasms
Overall rate | 3/26 (11.5%) | 3/27 (11.1%) | 6/27 (22.2%) | 7/27 (25.9%)
Adjusted rate | 11.5% | 11.6% | 23.7% | 27.3%
Terminal rate | 0/23 (0.0%) | 1/23 (4.3%) | 5/24 (20.8%) | 3/21 (14.3%)
First incidence (days) | 184 | 212 | 298 | 241
Poly-3 test | P=0.053 | P=0.663 | P=0.220 | P=0.139
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/26 (15.4%) | 7/27 (25.9%) | 8/27 (29.6%) | 8/27 (29.6%)
Adjusted rate | 15.4% | 27.0% | 31.6% | 31.2%
Terminal rate | 1/23 (4.3%) | 5/23 (21.7%) | 7/24 (29.2%) | 4/21 (19.0%)
First incidence (days) | 184 | 212 | 298 | 241
Poly-3 test | P=0.105 | P=0.248 | P=0.149 | P=0.154

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE A12 Summary of the Incidence of Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Disposition Summary
Animals initially in study | 26 | 27 | 27 | 27
Early deaths
Moribund | 1 | | | 1
Natural death | | 1 | 1
Survivors
Died last week of study | 2 | 3 | 2 | 5
Terminal kill | 23 | 23 | 24 | 21
Animals examined microscopically | 26 | 27 | 27 | 27
Alimentary System
Esophagus | (26) | (27) | (27) | (27)
Adventitia, necrosis | | 1 (4%)
Intestine large, cecum | (25) | (27) | (25) | (24)
Hyperplasia, lymphoid | 2 (8%) | 2 (7%) | 3 (12%) | 2 (8%)
Epithelium, hyperplasia | | | 1 (4%)
Intestine large, colon | (26) | (26) | (27) | (25)
Intestine large, rectum | (25) | (27) | (27) | (25)
Hyperplasia, lymphoid | | 1 (4%) | 1 (4%)
Intestine small, ileum | (25) | (27) | (25) | (25)
Intestine small, jejunum | (25) | (27) | (25) | (25)
Liver | (26) | (27) | (27) | (27)
Basophilic focus | | | | 1 (4%)
Hematopoietic cell proliferation | | | 1 (4%)
Infiltration cellular, lymphocyte | | | | 1 (4%)
Inflammation, chronic active | | 2 (7%) | 1 (4%)
Necrosis | | | 1 (4%)
Tension lipidosis | 3 (12%) | 5 (19%) | 7 (26%) | 4 (15%)
Vacuolization cytoplasmic | 6 (23%) | 4 (15%) | 3 (11%) | 10 (37%)
Mesentery | (1) | (0) | (1) | (1)
Hemorrhage | 1 (100%) | | | 1 (100%)
Fat, necrosis | | | 1 (100%) | 1 (100%)
Pancreas | (26) | (27) | (27) | (26)
Cytoplasmic alteration | | | | 1 (4%)
Infiltration cellular, lymphocyte | | | 1 (4%) | 3 (12%)
Acinar cell, degeneration | | | 1 (4%) | 1 (4%)
Salivary glands | (26) | (27) | (26) | (27)
Infiltration cellular, lymphocyte | 15 (58%) | 14 (52%) | 10 (38%) | 10 (37%)
Stomach, forestomach | (26) | (27) | (27) | (27)
Cardiovascular System
Heart | (26) | (27) | (27) | (26)
Bacterium | | 1 (4%)
Congestion | | | 2 (7%)
Inflammation, chronic active | 1 (4%) | | 1 (4%) | 1 (4%)
Pericardium, necrosis | | 1 (4%)
Endocrine System
Adrenal cortex | (26) | (27) | (27) | (26)
Subcapsular, hyperplasia | 25 (96%) | 25 (93%) | 27 (100%) | 24 (92%)
Parathyroid gland | (21) | (22) | (22) | (22)
Cyst | | 1 (5%)
Pituitary gland | (26) | (27) | (27) | (27)
Thyroid gland | (25) | (27) | (27) | (26)
Cyst | | 1 (4%)
Degeneration | 1 (4%) | 2 (7%)
Ectopic thymus | | 2 (7%) | | 1 (4%)
General Body System
Tissue NOS | (0) | (1) | (0) | (1)
Mediastinum, abscess | | | | 1 (100%)
Mediastinum, foreign body | | | | 1 (100%)
Genital System
Clitoral gland | (25) | (26) | (26) | (27)
Degeneration | | | | 1 (4%)
Ovary | (26) | (27) | (27) | (26)
Cyst | | 1 (4%) | 1 (4%) | 1 (4%)
Pigmentation | | | | 1 (4%)
Bilateral, cyst | | | 1 (4%)
Uterus | (26) | (27) | (27) | (27)
Edema | | | | 1 (4%)
Infiltration cellular, polymorphonuclear | 1 (4%) | 3 (11%) | 3 (11%) | 3 (11%)
Endometrium, hyperplasia, cystic | 3 (12%) | 4 (15%) | 5 (19%) | 5 (19%)
Lumen, dilatation | 10 (38%) | 12 (44%) | 14 (52%) | 8 (30%)
Vagina | (25) | (27) | (27) | (24)
Hematopoietic System
Bone marrow | (26) | (26) | (26) | (26)
Myeloid cell, hyperplasia | | | 4 (15%) | 1 (4%)
Lymph node | (1) | (1) | (0) | (3)
Lumbar, hyperplasia, lymphoid | 1 (100%) | | | 1 (33%)
Lymph node, mandibular | (26) | (27) | (25) | (26)
Hyperplasia, lymphoid | | | 2 (8%)
Lymph node, mesenteric | (26) | (26) | (26) | (27)
Hyperplasia, lymphoid | 8 (31%) | 6 (23%) | 6 (23%) | 6 (22%)
Spleen | (26) | (26) | (27) | (27)
Hematopoietic cell proliferation | 5 (19%) | 4 (15%) | 5 (19%) | 8 (30%)
Hyperplasia, lymphoid | 4 (15%) | 5 (19%) | 7 (26%) | 6 (22%)
Thymus | (24) | (26) | (23) | (27)
Bacterium | | 1 (4%)
Foreign body | | 1 (4%)
Hyperplasia, lymphoid | 3 (13%) | 2 (8%) | 3 (13%) | 2 (7%)
Inflammation, chronic active | | | | 1 (4%)
Necrosis | | 1 (4%)
Integumentary System
Mammary gland | (25) | (26) | (27) | (27)
Alveolus, hyperplasia | | 1 (4%)
Skin | (26) | (27) | (27) | (27)
Musculoskeletal System
Bone | (0) | (1) | (0) | (1)
Bone, femur | (26) | (27)
Skeletal muscle | (26) | (27) | (27) | (27)
Atrophy | 2 (8%)
Cyst | 1 (4%)
Nervous System
Brain, brain stem | (26) | (27) | (27) | (27)
Gliosis | | 1 (4%)
Brain, cerebrum | (26) | (27) | (27) | (27)
Compression | | | | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%)
Mineralization | | 1 (4%) | 4 (15%) | 2 (7%)
Peripheral nerve | (2) | (0) | (0) | (0)
Axon, degeneration | 2 (100%)
Spinal cord | (1) | (0) | (0) | (0)
Axon, degeneration | 1 (100%)
Respiratory System
Lung | (26) | (27) | (26) | (27)
Abscess | | | | 1 (4%)
Bacterium | | 1 (4%)
Foreign body | | | | 1 (4%)
Inflammation, chronic active | | | | 1 (4%)
Necrosis | | | | 1 (4%)
Mediastinum, foreign body | | 1 (4%)
Mediastinum, necrosis | | 1 (4%)
Nose | (26) | (27) | (27) | (27)
Special Senses System
Eye | (25) | (25) | (26) | (24)
Cataract | 1 (4%)
Harderian gland | (26) | (27) | (27) | (25)
Urinary System
Kidney | (26) | (27) | (27) | (27)
Casts protein | 1 (4%) | 1 (4%) | 3 (11%) | 2 (7%)
Cyst | 1 (4%) | | | 1 (4%)
Glomerulosclerosis | | | | 1 (4%)
Hydronephrosis | | | 1 (4%)
Infiltration cellular, lymphocyte | 9 (35%) | 6 (22%) | 5 (19%) | 4 (15%)
Inflammation, suppurative | | | 1 (4%)
Metaplasia, osseous | | 1 (4%)
Mineralization | 1 (4%)
Nephropathy | | | 1 (4%) | 1 (4%)
Ureter | (0) | (0) | (1) | (0)
Inflammation, suppurative | | | 1 (100%)
Lumen, dilatation | | | 1 (100%)
Urinary bladder | (26) | (27) | (27) | (26)
Infiltration cellular, lymphocyte | 1 (4%) | 4 (15%) | 2 (7%) | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A13 Summary of the Incidence of Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

| 0/0 mg/kg | 240/40 mg/kg
Disposition Summary
Animals initially in study | 24 | 25
Early deaths
Natural death | | 1
Survivors
Died last week of study | 1 | 2
Terminal kill | 23 | 22
Animals examined microscopically | 24 | 25
Alimentary System
Intestine large, cecum | (24) | (24)
Intestine large, rectum | (24) | (24)
Liver | (24) | (25)
Carcinoma, metastatic, pancreas | 1 (4%)
Hepatocellular adenoma | 3 (13%) | 5 (20%)
Hepatocellular carcinoma | | 2 (8%)
Pancreas | (23) | (25)
Acinar cell, carcinoma | 1 (4%)
Salivary glands | (24) | (25)
Cardiovascular System
Blood vessel | (24) | (24)
Heart | (24) | (25)
Endocrine System
Adrenal cortex | (24) | (25)
Islets, pancreatic | (23) | (25)
Thyroid gland | (24) | (24)
General Body System
Tissue NOS | (0) | (1)
Sarcoma, metastatic, skin | | 1 (100%)
Genital System
Epididymis | (24) | (24)
Preputial gland | (24) | (24)
Prostate | (24) | (25)
Seminal vesicle | (24) | (25)
Testes | (24) | (24)
Hematopoietic System
Bone marrow | (24) | (25)
Lymph node, mesenteric | (24) | (24)
Spleen | (24) | (24)
Thymus | (23) | (22)
Integumentary System
Skin | (24) | (25)
Subcutaneous tissue, sarcoma | | 1 (4%)
Musculoskeletal System
None
Nervous System
Brain, cerebrum | (24) | (25)
Respiratory System
Lung | (24) | (25)
Alveolar/bronchiolar adenoma | 2 (8%)
Nose | (24) | (25)
Special Senses System
Harderian gland | (24) | (25)
Adenoma | 1 (4%)
Urinary System
Kidney | (24) | (25)
Urinary bladder | (24) | (24)
Systemic Lesions
Multiple organs^b^ | (24) | (25)
Lymphoma malignant | | 2 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 10
Total primary neoplasms | 7 | 10
Total animals with benign neoplasms | 6 | 5
Total benign neoplasms | 6 | 5
Total animals with malignant neoplasms | 1 | 5
Total malignant neoplasms | 1 | 5
Total animals with metastatic neoplasms | 1 | 1
Total metastatic neoplasms | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A14 Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 3/24 (12.5%) | 5/25 (20.0%)
Adjusted rate^b^ | 12.8% | 21.3%
Terminal rate^c^ | 3/23 (13.0%) | 5/22 (22.7%)
First incidence (days) | 317 (T) | 317 (T)
Poly-3 test^d^ | | P=0.352
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/24 (12.5%) | 7/25 (28.0%)
Adjusted rate | 12.8% | 29.8%
Terminal rate | 3/23 (13.0%) | 7/22 (31.8%)
First incidence (days) | 317 (T) | 317 (T)
Poly-3 test | | P=0.143
All Organs: Malignant Lymphoma
Overall rate | 0/24 (0.0%) | 2/25 (8.0%)
Adjusted rate | 0.0% | 8.5%
Terminal rate | 0/23 (0.0%) | 1/22 (4.5%)
First incidence (days) | —^e^ | 300
Poly-3 test | | P=0.237
All Organs: Benign Neoplasms
Overall rate | 6/24 (25.0%) | 5/25 (20.0%)
Adjusted rate | 25.6% | 21.3%
Terminal rate | 6/23 (26.1%) | 5/22 (22.7%)
First incidence (days) | 317 (T) | 317 (T)
Poly-3 test | | P=0.498N
All Organs: Malignant Neoplasms
Overall rate | 1/24 (4.2%) | 5/25 (20.0%)
Adjusted rate | 4.2% | 20.8%
Terminal rate | 0/23 (0.0%) | 3/22 (13.6%)
First incidence (days) | 240 | 281
Poly-3 test | | P=0.093
All Organs: Benign or Malignant Neoplasms
Overall rate | 7/24 (29.2%) | 10/25 (40.0%)
Adjusted rate | 29.2% | 41.7%
Terminal rate | 6/23 (26.1%) | 8/22 (36.4%)
First incidence (days) | 240 | 281
Poly-3 test | | P=0.276

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE A15 Summary of the Incidence of Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

| 0/0 mg/kg | 240/40 mg/kg
Disposition Summary
Animals initially in study | 24 | 25
Early deaths
Natural death | | 1
Survivors
Died last week of study | 1 | 2
Terminal kill | 23 | 22
Animals examined microscopically | 24 | 25
Alimentary System
Intestine large, cecum | (24) | (24)
Hyperplasia, lymphoid | 3 (13%) | 1 (4%)
Intestine large, rectum | (24) | (24)
Degeneration, cystic | 1 (4%)
Liver | (24) | (25)
Cytomegaly | 18 (75%) | 14 (56%)
Eosinophilic focus | | 1 (4%)
Inflammation, chronic active | 1 (4%) | 1 (4%)
Necrosis | 2 (8%) | 1 (4%)
Tension lipidosis | 3 (13%) | 2 (8%)
Vacuolization cytoplasmic | 23 (96%) | 18 (72%)
Pancreas | (23) | (25)
Cytoplasmic alteration | 1 (4%)
Salivary glands | (24) | (25)
Infiltration cellular, lymphocyte | 8 (33%) | 8 (32%)
Cardiovascular System
Blood vessel | (24) | (24)
Heart | (24) | (25)
Endocrine System
Adrenal cortex | (24) | (25)
Hypertrophy | | 1 (4%)
Subcapsular, hyperplasia | 7 (29%) | 7 (28%)
Islets, pancreatic | (23) | (25)
Hyperplasia | 1 (4%) | 2 (8%)
Thyroid gland | (24) | (24)
Cyst | | 1 (4%)
Ectopic thymus | 1 (4%)
General Body System
Tissue NOS | (0) | (1)
Genital System
Epididymis | (24) | (24)
Hypospermia | | 1 (4%)
Serosa, inflammation, chronic active | 1 (4%)
Serosa, necrosis | 1 (4%)
Preputial gland | (24) | (24)
Abscess | | 1 (4%)
Degeneration | 1 (4%)
Duct, dilatation | | 1 (4%)
Prostate | (24) | (25)
Infiltration cellular, lymphocyte | 1 (4%) | 1 (4%)
Epithelium, hyperplasia | 1 (4%)
Seminal vesicle | (24) | (25)
Serosa, inflammation, chronic active | 1 (4%)
Testes | (24) | (24)
Spermatocele | | 1 (4%)
Interstitial cell, hyperplasia | 2 (8%) | 4 (17%)
Seminiferous tubule, degeneration | 2 (8%) | 2 (8%)
Hematopoietic System
Bone marrow | (24) | (25)
Myeloid cell, hyperplasia | | 2 (8%)
Lymph node, mesenteric | (24) | (24)
Hyperplasia, lymphoid | 15 (63%) | 12 (50%)
Spleen | (24) | (24)
Depletion lymphoid | 1 (4%)
Hematopoietic cell proliferation | 2 (8%) | 3 (13%)
Hyperplasia, lymphoid | 5 (21%) | 7 (29%)
Thymus | (23) | (22)
Degeneration | 1 (4%)
Hyperplasia, lymphoid | | 1 (5%)
Necrosis | | 1 (5%)
Integumentary System
Skin | (24) | (25)
Musculoskeletal System
None
Nervous System
Brain, cerebrum | (24) | (25)
Mineralization | 6 (25%) | 3 (12%)
Respiratory System
Lung | (24) | (25)
Foreign body | | 1 (4%)
Infiltration cellular, polymorphonuclear | | 1 (4%)
Bronchiole, epithelium, hyperplasia | | 1 (4%)
Nose | (24) | (25)
Foreign body | | 1 (4%)
Inflammation, suppurative | | 1 (4%)
Special Senses System
Harderian gland | (24) | (25)
Urinary System
Kidney | (24) | (25)
Infiltration cellular, lymphocyte | 6 (25%) | 6 (24%)
Mineralization | | 1 (4%)
Capsule, inflammation, chronic active | 1 (4%)
Pelvis, dilatation | | 1 (4%)
Renal tubule, regeneration | 2 (8%) | 3 (12%)
Urinary bladder | (24) | (24)
Infiltration cellular, lymphocyte | | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A16 Summary of the Incidence of Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

| 0/0 mg/kg | 240/40 mg/kg
Disposition Summary
Animals initially in study | 26 | 26
Survivors
Died last week of study | 1 | 3
Terminal kill | 25 | 23
Animals examined microscopically | 26 | 26
Alimentary System
Intestine large, cecum | (25) | (26)
Liver | (25) | (26)
Salivary glands | (25) | (26)
Cardiovascular System
Heart | (25) | (26)
Endocrine System
Adrenal cortex | (26) | (26)
Thyroid gland | (26) | (26)
General Body System
None
Genital System
Ovary | (26) | (26)
Teratoma malignant | 1 (4%)
Yolk sac carcinoma | 1 (4%)
Uterus | (26) | (26)
Polyp stromal | 1 (4%) | 1 (4%)
Sarcoma stromal | | 1 (4%)
Vagina | (26) | (25)
Hematopoietic System
Bone marrow | (25) | (26)
Lymph node | (0) | (2)
Lymph node, mandibular | (25) | (25)
Lymph node, mesenteric | (25) | (26)
Spleen | (26) | (26)
Thymus | (25) | (25)
Integumentary System
Mammary gland | (26) | (26)
Adenoma | 1 (4%)
Musculoskeletal System
None
Nervous System
Brain, brain stem | (26) | (26)
Astrocytoma malignant | | 1 (4%)
Brain, cerebellum | (26) | (26)
Astrocytoma malignant | | 1 (4%)
Brain, cerebrum | (26) | (26)
Respiratory System
Lung | (26) | (26)
Yolk sac carcinoma, metastatic, ovary | 1 (4%)
Special Senses System
Harderian gland | (25) | (26)
Urinary System
Kidney | (25) | (26)
Urinary bladder | (25) | (26)
Systemic Lesions
Multiple organs^b^ | (26) | (26)
Leukemia, granulocytic | | 1 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 4 | 4
Total primary neoplasms | 4 | 5
Total animals with benign neoplasms | 2 | 1
Total benign neoplasms | 2 | 1
Total animals with malignant neoplasms | 2 | 3
Total malignant neoplasms | 2 | 4
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A17 Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
All Organs: Granulocytic Leukemia
Overall rate^a^ | 0/26 (0.0%) | 1/26 (3.8%)
Adjusted rate^b^ | 0.0% | 4.1%
Terminal rate^c^ | 0/25 (0.0%) | 1/23 (4.3%)
First incidence (days) | —^e^ | 320 (T)
Poly-3 test^d^ | | P=0.493
All Organs: Benign Neoplasms
Overall rate | 2/26 (7.7%) | 1/26 (3.8%)
Adjusted rate | 7.8% | 4.1%
Terminal rate | 2/25 (8.0%) | 1/23 (4.3%)
First incidence (days) | 320 (T) | 318 (T)
Poly-3 test | | P=0.512N
All Organs: Malignant Neoplasms
Overall rate | 2/26 (7.7%) | 3/26 (11.5%)
Adjusted rate | 7.7% | 11.9%
Terminal rate | 1/25 (4.0%) | 2/23 (8.7%)
First incidence (days) | 259 | 260
Poly-3 test | | P=0.484
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/26 (15.4%) | 4/26 (15.4%)
Adjusted rate | 15.4% | 15.9%
Terminal rate | 3/25 (12.0%) | 3/23 (13.0%)
First incidence (days) | 259 | 260
Poly-3 test | | P=0.628

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE A18 Summary of the Incidence of Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

| 0/0 mg/kg | 240/40 mg/kg
Disposition Summary
Animals initially in study | 26 | 26
Survivors
Died last week of study | 1 | 3
Terminal kill | 25 | 23
Animals examined microscopically | 26 | 26
Alimentary System
Intestine large, cecum | (25) | (26)
Hyperplasia, lymphoid | 3 (12%)
Liver | (25) | (26)
Basophilic focus | | 1 (4%)
Infiltration cellular, lymphocyte | 2 (8%) | 1 (4%)
Inflammation, chronic active | 2 (8%)
Tension lipidosis | 3 (12%) | 4 (15%)
Vacuolization cytoplasmic | 12 (48%) | 6 (23%)
Salivary glands | (25) | (26)
Infiltration cellular, lymphocyte | 15 (60%) | 12 (46%)
Cardiovascular System
Heart | (25) | (26)
Endocrine System
Adrenal cortex | (26) | (26)
Subcapsular, hyperplasia | 23 (88%) | 24 (92%)
Thyroid gland | (26) | (26)
Degeneration | | 1 (4%)
Ectopic thymus | 2 (8%) | 1 (4%)
General Body System
None
Genital System
Ovary | (26) | (26)
Cyst | 4 (15%) | 1 (4%)
Uterus | (26) | (26)
Infiltration cellular, polymorphonuclear | 1 (4%)
Endometrium, hyperplasia, cystic | 4 (15%) | 3 (12%)
Lumen, dilatation | 16 (62%) | 13 (50%)
Vagina | (26) | (25)
Hematopoietic System
Bone marrow | (25) | (26)
Lymph node | (0) | (2)
Renal, hyperplasia, lymphoid | | 1 (50%)
Lymph node, mandibular | (25) | (25)
Hyperplasia, lymphoid | | 1 (4%)
Lymph node, mesenteric | (25) | (26)
Hyperplasia, lymphoid | 4 (16%) | 3 (12%)
Spleen | (26) | (26)
Hematopoietic cell proliferation | 2 (8%) | 2 (8%)
Hyperplasia, lymphoid | 6 (23%) | 6 (23%)
Thymus | (25) | (25)
Cyst, multiple | | 1 (4%)
Hyperplasia, lymphoid | 1 (4%) | 3 (12%)
Integumentary System
Mammary gland | (26) | (26)
Musculoskeletal System
None
Nervous System
Brain, brain stem | (26) | (26)
Brain, cerebellum | (26) | (26)
Brain, cerebrum | (26) | (26)
Mineralization | 2 (8%) | 4 (15%)
Respiratory System
Lung | (26) | (26)
Infiltration cellular, lymphocyte | | 1 (4%)
Inflammation, chronic active | | 1 (4%)
Special Senses System
Harderian gland | (25) | (26)
Urinary System
Kidney | (25) | (26)
Infiltration cellular, lymphocyte | 9 (36%) | 5 (19%)
Urinary bladder | (25) | (26)
Infiltration cellular, lymphocyte | 2 (8%) | 3 (12%)
Lumen, dilatation | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion