# REFERENCES

The Aldrich Library of Infrared Spectra (1981). 3rd ed. (C.J. Pouchert, Ed.), Spectrum 136E. Aldrich Chemical Company, Inc., Milwaukee, WI.
The Aldrich Library of NMR Spectra (1983). 2nd ed. (C.J. Pouchert, Ed.), Spectrum No. 195A. Aldrich Chemical Company, Inc., Milwaukee, WI.
The Aldrich Library of FT IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Spectrum 1:232B. Aldrich Chemical Company, Inc., Milwaukee, WI.
Armitage, P. (1971). Statistical Methods in Medical Research, pp. 362–365. John Wiley and Sons, Inc., New York.
Belinsky, S.A., Nikula, K.J., Pamisano, W.A., Michels, R., Saccomanno, G., Gabrielson, E., Baylin, S.B., and Herman, J.G. (1998). Aberrant methylation of p16^INK4a^ is an early event in lung cancer and potential biomarker for early diagnosis. Proc. Natl. Acad. Sci. 95, 11,891–11,896.
Bishop, J.B., Morris, R.W., Seely, J.C., Hughes, L.A., Cain, K.T., and Generoso, W.M. (1997). Alterations in the reproductive patterns of female mice exposed to xenobiotics. Fundam. Appl. Toxicol. 40, 191–204.9441715
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Canter, D.A., Zeiger, E., Haworth, S., Lawlor, T., Mortelmans, K., and Speck, W. (1986). Comparative mutagenicity of aliphatic epoxides in Salmonella. Mutat. Res. 172, 105–138.3531837
Code of Federal Regulations (CFR) 21, Part 58.
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Dixon, W.J., and Massey, F.J., Jr. (1957). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Ellison, D., Love, S., Chimelli, L., Harding, B., Lowe, J.S., and Vinters, H. (2004). Adult hypoxic and ischemic lesions. In Neuropathology: A Reference Text of CNS Pathology, 2nd ed., pp. 163–237. Mosby, New York.
Foureman, P., Mason, J.M., Valencia, R., and Zimmering, S. (1994). Chemical mutagenesis testing in Drosophila. X. Results of 70 coded chemicals tested for the National Toxicology Program. Environ. Mol. Mutagen. 23, 208–227.8162896
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Hazardous Substances Data Bank (HSDB) (2006). National Institute for Occupational Safety and Health, available through the National Library of Medicine TOXNET System.
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC 27707.
International Agency for Research on Cancer (IARC) (2000). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Some Industrial Chemicals. Vol. 77. IARC, Lyon, France.
International Life Sciences Institute (ILSI) (2001). Alternatives to Carcinogenicity Testing. Toxicol. Pathol. 29 (Suppl. epilogue), 196–197.
Jackson, E.L., Olive, K.P., Tuveson, D.A., Bronson, R., Crowley, D., Brown, M., and Jacks, T. (2005). The differential effects of mutant p53 alleles on advanced murine lung cancer. Cancer Res. 65, 10,280–10,288.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Jones, A.R. (1975). The metabolism of 3-chloro-, 3-bromo- and 3-iodopropan-1,2-diol in rats and mice. Xenobiotica 5, 155–165.1166663
Jones, A.R., and O’Brien, R.W. (1980). Metabolism of three active analogues of the male anti-fertility agent α-chlorohydrin in the rat. Xenobiotica 10, 365–370.7415219
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Lachat, Y., Diserens, A.C., Nozaki, M., Kobayashi, H., Hamou, M.F., Godard, S., de Tribolet, N., and Hegi, M.E. (2004). INK4a/Arf is required for suppression of EGFR/)EGFR (2-7)-dependent ERK activation in mouse astrocytes and glioma. Oncogene 23, 6854–6863.15273738
Lowe, S.W., and Sherr, C.J. (2003). Tumor suppression by Ink4a/Arf: Progress and puzzles. Curr. Opin. Genet. Dev. 13, 77–83.12573439
Lubet, R., Wang, Y., Zhang, Z., and You, M. (2005). Mouse models incorporating alterations in the major tumor suppressor genes p53 and p16: Their use in screening for potential carcinogens, developing further relevant mouse models, and screening for potential chemopreventive and chemotherapeutic agents. Exp. Lung Res. 31, 117–133.15765922
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
March, G. (1978). Advanced Organic Chemistry. John Wiley & Sons, Inc., New York.
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Morrison, D.F. (1976). Multivariate Statistical Methods, 2nd ed., pp. 170–179. McGraw-Hill Book Company, New York.
National Center for Biotechnology Information (NCBI) (2005). Unigene, http://www.ncbi.nlm.nih.gov/entrez/query.fcgi?CMD=search&DB=unigene.
National Institute for Occupational Safety and Health (NIOSH) (1990). National Occupational Exposure Survey (1981-1983), unpublished provisional data as of July 1, 1990. NIOSH, Cincinnati, OH.
National Toxicology Program (NTP) (1986). Toxicology and Carcinogenesis Studies of Benzene (CAS No. 71-43-2) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 289. NIH Publication No. 86-2545. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1990). Toxicology and Carcinogenesis Studies of Glycidol (CAS No. 556-52-5) in F344/N Rats and B6C3F_1_ Mice. Technical Report Series No. 374. NIH Publication No. 90-2829. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1996). Toxicology and Carcinogenesis Studies of Phenolphthalein (CAS No. 77-09-8) in F344/N Rats and B6C3F_1_ Mice (Feed Studies). Technical Report Series No. 465. NIH Publication No. 97-3390. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2004). Report on Carcinogens, 11th ed., pp. 130–131. U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology and Carcinogenesis Study of Benzene (CAS No. 71-43-2) in Genetically Modified Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Gavage Study). GMM Report Series No. 8. NIH Publication No. 08-4425. National Institutes of Health, Research Triangle Park, NC, Public Health Service, U.S. Department of Health and Human Services.
National Toxicology Program (NTP) (2007b). Toxicology and Carcinogenesis Study of Phenolphthalein (CAS No. 77-09-8) in Genetically Modified Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Gavage Study). GMM Report Series No. 12. NIH Publication No. 08-5961. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC (in press).
Norppa, H., Hemminki, K., Sorsa, M., and Vainio, H. (1981). Effect of monosubstituted epoxides on chromosome aberrations and SCE in cultured human lymphocytes. Mutat. Res. 91, 243–250.7242554
Patel, J.M., Wood, J.C., and Leibman, K.C. (1980). The biotransformation of allyl alcohol and acrolein in rat liver and lung preparations. Drug Metab. Dispos. 8, 305–308.6107226
Quelle, D.E., Zindy, F., Ashmun, R.A., and Sherr, C.J. (1995). Alternative reading frames of the INK4a tumor suppressor gene encode two unrelated proteins capable of inducing cell cycle arrest. Cell 83, 993–1000.8521522
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Rodin, S.N., and Rodin, A.S. (2005). Origins and selection of p53 mutations in lung carcinogenesis. Sem. Cancer Bio. 15, 103–112.
Seilkop, S.K. (1995). The effect of body weight on tumor incidence and carcinogenicity testing in B6C3F_1_ mice and F344 rats. Fundam. Appl. Toxicol. 24, 247–259.7737436
Serrano, M., Hannon, G.J., and Beach, D. (1993). A new regulatory motif in cell-cycle control causing specific inhibition of cyclin D/CDK4. Nature 366, 704–707.8259215
Serrano, M., Lee, H.W., Chin, L., Cordon-Cardo, C., Beach, D., and DePinho, R.A. (1996). Role of the INK4a locus in tumor suppression and cell mortality. Cell 85, 27–37.8620534
Sharpless, N.E. (2005). INK4a/ARF: A multifunctional tumor suppressor locus. Mutat. Res. 576, 22–38.15878778
Sharpless, N.E., and DePinho, R.A. (1999). The INK4A/Arf locus and its two gene products. Curr. Opin. Genet. Dev. 9, 22–30.10072356
Sharpless, N.E., Bardeesy, N., Lee, K.G., Carrasco, D., Castrillon, D.H., Aguirre, A.J., Wu, E.A., Horner, J.W., and DePinho, R.A. (2001). Loss of p16^Ink4a^ with retention of p19^Arf^ predisposes mice to tumorigenesis. Nature 413, 86–91.11544531
Sharpless, N.E., Alson, S., Chan, S., Silver, D.P., Castrillon, D.H., and DePinho, R.A. (2002). P16^INK4a^ and p53 deficiency cooperate in tumorigenesis. Cancer Res. 62, 2761–2765.12019151
Sherr, C.J., and McCormick, F. (2002). The RB and p53 pathways in cancer. Cancer Cell 2, 103–112.12204530
Sherr, C.J., and Weber, J.D. (2000). The Arf/p53 pathway. Curr. Opin. Genet. Dev. 10, 94–99.10679383
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Slott, V.L., and Hales, B.F. (1985). Teratogenicity and embryolethality of acrolein and structurally related compounds in rats. Teratology 32, 65–72.4035593
Tam, A.S., Devereux, T.R., Patel, A.C., Foley, J.F., Maronpot, R.R., and Massey, T.E. (2003). Perturbations of the Ink4a/Arf gene locus in aflatoxin B_1_-induced mouse lung tumors. Carcinogenesis 24, 121–132.12538357
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150
Thompson, E.D., and Gibson, D.P. (1984). A method for determining the maximum tolerated dose for acute in vivo cytogenetic studies. Food Chem. Toxicol. 22, 665–676.6540742
Toyooka, S., Tsuda, T., and Gazdar, A.F. (2003). The TP53 gene, tobacco exposure, and lung cancer. Hum. Mutat. 21, 229–239.12619108
Uhrbom, L., Dai, C., Celestino, J.C., Rosenblum, M.K., Fuller, G.N., and Holland, E.C. (2002). Ink4a-Arf loss cooperates with Kras activation in astrocytes and neural progenitors to generate glioblastomas of various morphologies depending on activated Akt. Cancer Res. 62, 5551–5558.12359767
Wang, Y., Zhang, Z., Kastens, E., Lubet, R.A., and You, M. (2003). Mice with alterations in both p53 and Ink4a/Arf display a striking increase in lung tumor multiplicity and progression: Differential chemopreventive effect of budesonide in wild-type and mutant A/J mice. Cancer Res. 63, 4389–4395.12907609
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zerodose control. Biometrics 42, 183–186.3719054
Yokota, J., and Kohno, T. (2004). Molecular footprints of human lung cancer progression. Cancer Sci. 95, 197–204.15016317