# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On August 28, 2006, the draft Report on the toxicology and carcinogenesis study of glycidol received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences (NIEHS), Research Triangle Park, NC.

Dr. J.K. Dunnick, NIEHS, introduced the study of glycidol in haploinsufficient p16^Ink4a^/p19^Arf^ mice by reviewing the uses of the chemical, the previous NTP carcinogenicity findings, the design and dose selection for the genetically modified mouse model studies, and the nonneoplastic and neoplastic lesions observed in the 40-week study. The proposed conclusions were clear evidence of carcinogenic activity of glycidol in male haploinsufficient p16^Ink4a^/p19^Arf^ mice and some evidence of carcinogenic activity of glycidol in female haploinsufficient p16^Ink4a^/p19^Arf^ mice.

Dr. Mirsalis, the first principal reviewer, felt the study was well conducted and agreed with the proposed conclusions. He asked for addition of a dose selection rationale section and for explanation of the survival statistics used.

Dr. Giesy, the second principal reviewer, had no further comments.

Dr. Deininger, the third principal reviewer, noted that the main evidence for this study came from histiocytic sarcomas, which have a naturally high background rate.

Dr. Dunnick noted the dose selection was included in the review of prior studies and would be more clearly identified. Dr. G.E. Kissling, NIEHS, said the survival statistics were based on the total survival time for all the animals in a group rather than on the number of animals surviving to study termination.

Dr. Sikka asked if a mechanism or known metabolite was known to be responsible for the carcinogenic activity of glycidol. Dr. Walker answered that, as an epoxide, the chemical acted directly with DNA. Dr. Walker also cautioned about use of the term “potent” in citing literature statements about the carcinogenicity of glycidol.

Dr. Mirsalis moved, and Dr. Deininger seconded, that the conclusions be accepted as written. The motion was approved unanimously with seven votes.