# DISCUSSION AND CONCLUSIONS

In the current study, glycidol caused a detectable carcinogenic response in the haploinsufficient p16^Ink4a^/p19^Arf^ mouse in a shorter time period and with fewer animals than glycidol did in the 2-year NTP studies (NTP, 1990).

Survival of male and female mice in the 25, 50, and 100 mg/kg groups was not statistically different from that of the vehicle controls, although there were fewer numbers of dosed male and female mice surviving until the end of the study. Mean body weights of male and female mice in the 200 mg/kg groups were less than those of the vehicle controls throughout most of the study. These effects were considered to be related to the toxic and carcinogenic effects of glycidol.

After 40 weeks of glycidol administration, the incidences of histiocytic sarcoma were significantly increased in male mice in the 50 and 200 mg/kg groups (13%, 40%, 60%, 33%, and 73%, respectively, for the 0, 25, 50, 100, and 200 mg/kg groups). The incidences of histiocytic sarcoma in the 25 and 100 mg/kg groups were also increased, although they were not significant by the Fisher exact test. The incidence of histiocytic sarcoma in dosed male mice was significant by the Cochran-Armitage trend test, and the incidences in all dosed groups were greater than those in the current vehicle controls and the historical controls (13% in two studies). This was considered clear evidence of carcinogenic activity. In female mice, there was a greater background for histiocytic sarcoma [current controls: 60%; historical controls: 47% (range 33% to 60%)], and there was no statistically significant increase in the incidence of histiocytic sarcoma in any dosed group.

The incidence of alveolar/bronchiolar adenoma (27%) was significantly increased in 200 mg/kg female mice. The occurrence of these lung neoplasms was considered to be some evidence for a carcinogenic effect because the effect was significant by the trend statistic and was greater than the incidence in the current (0%) and historical controls (mean 3%, range 0% to 7%; Appendix F). This was not considered to be clear evidence of a carcinogenic effect because the incidence of alveolar/bronchiolar carcinoma was not significantly increased in any dosed group by pairwise comparisons with the vehicle controls.

In male mice, the incidence of alveolar/bronchiolar adenoma was significantly increased in the 100 mg/kg group. However, because the incidence of lung neoplasms was not also increased in the 200 mg/kg group, this was not considered to be clearly related to treatment. In the 200 mg/kg male group, the decreased body weight relative to controls (i.e., 79% of controls) may have been one factor in the failure to see an increase in the incidence of lung neoplasms in this group (Seilkop, 1995).

The few forestomach squamous cell papillomas seen in dosed female mice may have been related to treatment. The irritant effects of glycidol in the forestomach, as demonstrated by the occurrence of forestomach ulcers and/or hyperplasia in glycidol treated groups, may have contributed to the development of the forestomach papillomas.

Deletion of one functional p16 gene in this mouse model affects two pathways leading to cancer — the p53 (P53, MDM2, and ARF) and Rb (Rb, P16, P14, P21, cyclin D1 CyclinE) pathways, two of the most common pathways altered in cancer (Sherr and McCormick, 2002; Lowe and Sherr, 2003). Defects in the p53 and p16 pathways are part of the multiple genetic changes that lead to lung cancer (Yokota and Kohno, 2004), and defects in these two pathways often occur simultaneously in lung cancer (Belinsky et al., 1998; Toyooka et al., 2003; Lubet et al., 2005; Rodin and Rodin, 2005). Deficiencies in both pathways increase the rate of tumor formation in mice compared with deficiency in just one pathway (Sharpless et al., 2002). Both Ink4/Arf gene alterations occur in aflatoxin- (Tam et al., 2003) and urethane- (Sharpless et al., 2001) induced mouse lung tumors, adding to the evidence that two tumor gene pathways are inactivated in lung cancers. Other studies suggest that when two genes are altered/mutated [e.g., K-ras and p53 (Tam et al., 2003) or p53 and Ink4a/Arf (Wang et al., 2003)], mice become more susceptible to formation of lung tumors (Jackson et al., 2005).

Glycidol has also been shown to cause neuronopathy in B6C3F_1_ mice and F344/N rats in 90-day gavage studies at 150 mg/kg or greater (Little and Sills, 2003) but not at lower doses (75 mg/kg or less) after 2 years of gavage (NTP, 1990). In the 90-day studies, glycidol induced neuronopathy in B6C3F_1_ mice and F344/N rats similar to that of p16 deficient mice including acute neuronal necrosis and depletion in various specific brain nuclei (NTP, 1990; Dr. Peter Little, personal communication). The distribution and nature of the neuronal lesions was not considered consistent with those induced by ischemia/hypoxemia. In ischemia/hypoxemia, neurons in the lateral parietal cortex, CA1 region of the hippocampus, caudate/putamen, anterior lateral thalamus, and Purkinje cells are primarily affected (Ellison et al., 2004). In the glycidol treated mice (B6C3F_1_ and p16 deficient mice), lesions were seen in the oculomotor, red, cerebellar roof, vestibular, medullary, and reticular gray nuclei. In addition to these regions, glycidol induced lesions in Purkinje cells and lateral superior olivary nuclei in the rat. The findings indicate that glycidol at relatively higher doses (greater than 100 mg/kg) targets specific neuronal populations in B6C3F_1_ mice, F344/N rats, and p16 deficient mice.

In the 2-year studies, glycidol induced gliomas in rats (NTP, 1990). However, p16^Ink4a^/p19^Arf^ gene deficiency was not sufficient for glycidol induction of brain tumors in mice. Other studies suggest that p16^Ink4a^/p19^Arf^ tumor suppressor gene deficiency needs to be combined with oncogene activation for the formation of brain tumors in mice. K-ras (Uhrbom et al., 2002) and epidermal growth factor receptor amplification (Lachat et al., 2004) are some of the other gene changes that combined with the p16^Ink4a^/p19^Arf^ tumor suppressor gene deficiency lead to gliomas in mice.

Glycidol was strongly mutagenic in a number of Salmonella typhimurium tester strains, and it induced gene mutations and chromosomal damage in mammalian cells in vitro, with over 80% of all cells showing chromosomal aberrations at concentrations of 50 µg/mL or greater (NTP, 1990); additional positive responses were seen in Drosophila germ cell assays and acute micronucleus tests in B6C3F_1_ mice (NTP, 1990). Although glycidol induced increased frequencies of micronucleated erythrocytes in the haploinsufficient p16^Ink4a^/p19^Arf^ mice used in this gavage study, the increases were small and were not consistently detected until the 26-week sampling time, which is unusual considering that the circulating normochromatic erythrocyte population typically reaches steady state within about 30 days following the start of exposure. The weak, delayed micronuclei response seen with glycidol in the haploinsufficient p16^Ink4a^/p19^Arf^ mouse, compared with the potent responses it induces in vitro, suggest that glycidol, particularly when administered by gavage, might not reach the bone marrow target site for erythrocyte micronuclei induction in amounts sufficient to produce a robust response.

This current glycidol haploinsufficient p16^Ink4a^/p19^Arf^ mouse study detected fewer carcinogenic target sites than the 2-year glycidol B6C3F_1_ mouse study (NTP, 1990). The carcinogenic responses in the glycidol haploinsufficient p16^Ink4a^/p19^Arf^ study were seen at 50, 100, and 200 mg/kg in the male mouse (histiocytic sarcomas and alveolar/bronchiolar adenomas at 100 mg/kg) and in female mice at 200 mg/kg (alveolar/bronchiolar adenomas). The glycidol carcinogenic response in the 2-year B6C3F_1_ mouse study occurred at 25 and 50 mg/kg. The total glycidol dose administered in the 40-week haploinsufficient p16^Ink4a^/p19^Arf^ study at the carcinogenic dose of 50 mg/kg was 14,000 mg glycidol/kg, and the total glycidol dose administered to B6C3F_1_ mice in the 2-year study at the carcinogenic dose of 25 mg/kg was 18,200 mg glycidol/kg.

## Conclusions

Under the conditions of this 40-week gavage study, there was clear evidence of carcinogenic activity^*^ of glycidol in male haploinsufficient p16^Ink4a^/p19^Arf^ mice based on the occurrence of histiocytic sarcomas. The increased incidences of alveolar/bronchiolar adenomas in male mice were also considered to be related to glycidol administration. There was some evidence of carcinogenic activity of glycidol in haploinsufficient p16^Ink4a^/p19^Arf^ female mice based on the occurrence of alveolar/bronchiolar adenoma. The occurrence of forestomach papillomas in female mice may also have been related to glycidol administration.

Treatment of male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice with glycidol was associated with forestomach hyperplasia and neuronopathy in the brain.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 8. A summary of the Technical Reports Review Subcommittee comments and the public discussion on this Report appears on page 10.