# RESULTS

## Mice 40-Week Study

### Survival

Estimates of 40-week survival probabilities for male and female mice are shown in Table 3. Although survival of males and females administered 200 mg glycidol/kg body weight was less than that of the vehicle controls, the differences were not statistically significant. Survival of the other dosed groups was similar to that of the vehicle controls.

### Body Weights, Clinical Findings, Organ Weights, and Sperm Evaluation

Mean body weights of 200 mg/kg males and 100 and 200 mg/kg females were less than those of the vehicle controls after weeks 4, 14, and 12, respectively (Figure 3 and Tables 4 and 5). The final mean body weights of 25 and 50 mg/kg female mice were 94% and 88% that of the vehicle controls, respectively. Treatment-related clinical findings in 200 mg/kg males and females included lethargy, abnormal breathing, and tremors.

Compared to the vehicle controls, absolute organ weights were significantly decreased in the heart and right testis of 200 mg/kg male mice and in the thymus of 200 mg/kg female mice (Table C1). There were also significant decreases in the left testis, left epididymis, and left cauda epididymis weights of 200 mg/kg males accompanied by a significant decrease in the number of sperm heads per cauda epididymis (Table D1). There were no treatment-related histopathologic abnormalities in the testis.

TABLE 3 Survival of Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15
Accidental death^a^ | 0 | 0 | 0 | 0 | 1
Moribund | 0 | 0 | 1 | 0 | 4
Natural deaths | 2 | 1 | 1 | 1 | 3
Animals surviving to study termination | 13 | 14 | 13 | 14 | 7
Percent probability of survival at end of study^b^ | 87 | 93 | 87 | 93 | 51
Mean survival (days)^c^ | 272 | 278 | 269 | 275 | 251
Survival analysis^d^ | P=0.006 | P=0.951N | P=1.000N | P=0.984N | P=0.096
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15
Moribund | 2 | 1 | 2 | 1 | 4
Natural deaths | 0 | 0 | 1 | 0 | 2
Animals surviving to study termination | 13 | 14 | 12 | 14 | 9
Percent probability of survival at end of study | 87 | 93 | 80 | 93 | 60
Mean survival (days) | 267 | 278 | 275 | 278 | 257
Survival analysis | P=0.045 | P=0.984N | P=0.999 | P=0.984N | P=0.226

a Censored from survival analysis

b Kaplan-Meier determinations

c Mean of all deaths (uncensored, censored, and terminal sacrifice)

d The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A lower mortality in a dosed group is indicated by N.

FIGURE 3 Growth Curves for Male and Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice Administered Glycidol by Gavage for 40 Weeks

TABLE 4 Mean Body Weights and Survival of Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg | | | 200 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 27.4 | 15 | 27.0 | 99 | 15 | 27.3 | 100 | 15 | 27.1 | 99 | 15 | 27.5 | 100 | 15
2 | 27.8 | 15 | 28.0 | 101 | 15 | 28.2 | 101 | 15 | 28.0 | 101 | 15 | 28.1 | 101 | 15
3 | 28.9 | 15 | 28.6 | 99 | 15 | 29.1 | 101 | 15 | 28.7 | 99 | 15 | 28.5 | 99 | 15
4 | 30.3 | 15 | 29.6 | 98 | 15 | 30.3 | 100 | 15 | 29.3 | 97 | 15 | 29.4 | 97 | 15
5 | 31.4 | 15 | 30.4 | 97 | 15 | 30.4 | 97 | 15 | 30.3 | 97 | 15 | 29.5 | 94 | 15
6 | 31.9 | 15 | 31.0 | 97 | 15 | 31.2 | 98 | 15 | 30.7 | 96 | 15 | 29.2 | 92 | 15
7 | 33.0 | 15 | 32.7 | 99 | 15 | 33.2 | 101 | 15 | 32.1 | 97 | 15 | 30.2 | 92 | 15
8 | 33.8 | 15 | 33.2 | 98 | 15 | 34.0 | 101 | 15 | 32.5 | 96 | 15 | 30.5 | 90 | 15
9 | 34.0 | 15 | 33.2 | 98 | 15 | 34.6 | 102 | 15 | 33.1 | 97 | 15 | 30.7 | 90 | 15
10 | 36.2 | 15 | 34.1 | 94 | 15 | 35.9 | 99 | 15 | 34.7 | 96 | 15 | 31.5 | 87 | 15
11 | 36.6 | 15 | 35.0 | 96 | 15 | 36.0 | 98 | 15 | 34.8 | 95 | 15 | 31.2 | 85 | 15
12 | 36.0 | 15 | 35.6 | 99 | 15 | 37.0 | 103 | 15 | 35.3 | 98 | 15 | 31.4 | 87 | 15
13 | 36.4 | 15 | 37.0 | 102 | 15 | 37.5 | 103 | 15 | 36.6 | 101 | 15 | 32.7 | 90 | 15
14 | 38.0 | 15 | 37.8 | 100 | 15 | 38.4 | 101 | 15 | 36.7 | 97 | 15 | 32.5 | 86 | 15
15 | 38.8 | 15 | 38.8 | 100 | 15 | 39.4 | 102 | 15 | 37.5 | 97 | 15 | 33.9 | 87 | 15
16 | 40.4 | 15 | 39.4 | 98 | 15 | 40.6 | 101 | 15 | 38.6 | 96 | 15 | 34.0 | 84 | 15
17 | 41.7 | 15 | 40.1 | 96 | 15 | 41.7 | 100 | 15 | 39.5 | 95 | 15 | 34.7 | 83 | 15
18 | 41.9 | 15 | 41.0 | 98 | 15 | 42.8 | 102 | 15 | 40.1 | 96 | 15 | 34.8 | 83 | 15
19 | 42.6 | 15 | 41.0 | 96 | 15 | 43.2 | 101 | 15 | 39.8 | 93 | 15 | 35.0 | 82 | 15
20 | 43.3 | 15 | 41.9 | 97 | 15 | 43.2 | 100 | 15 | 40.8 | 94 | 15 | 35.7 | 82 | 15
21 | 43.1 | 15 | 41.3 | 96 | 15 | 42.3 | 98 | 15 | 40.8 | 95 | 15 | 35.5 | 82 | 15
22 | 44.3 | 15 | 42.8 | 97 | 15 | 43.1 | 97 | 14 | 42.1 | 95 | 15 | 36.8 | 83 | 15
23 | 44.6 | 15 | 42.5 | 95 | 15 | 44.6 | 100 | 14 | 42.6 | 96 | 15 | 37.0 | 83 | 15
24 | 45.2 | 15 | 42.8 | 95 | 15 | 44.5 | 99 | 14 | 43.2 | 96 | 15 | 36.8 | 81 | 15
25 | 45.4 | 15 | 42.7 | 94 | 15 | 44.6 | 98 | 14 | 43.2 | 95 | 15 | 36.4 | 80 | 15
26 | 45.9 | 15 | 43.7 | 95 | 15 | 45.0 | 98 | 14 | 44.1 | 96 | 15 | 37.7 | 82 | 15
27 | 46.1 | 15 | 44.2 | 96 | 15 | 45.7 | 99 | 14 | 44.0 | 95 | 15 | 37.7 | 82 | 14
28 | 46.0 | 15 | 44.5 | 97 | 15 | 45.8 | 100 | 14 | 44.0 | 96 | 15 | 37.7 | 82 | 14
29 | 46.3 | 14 | 44.6 | 96 | 15 | 46.3 | 100 | 14 | 44.0 | 95 | 15 | 37.5 | 81 | 14
30 | 46.4 | 14 | 45.1 | 97 | 15 | 46.5 | 100 | 14 | 45.0 | 97 | 14 | 36.4 | 78 | 14
31 | 47.8 | 14 | 46.1 | 96 | 15 | 47.5 | 99 | 14 | 45.9 | 96 | 14 | 37.4 | 78 | 12
32 | 47.3 | 14 | 46.3 | 98 | 15 | 47.3 | 100 | 14 | 45.9 | 97 | 14 | 39.3 | 83 | 10
33 | 47.7 | 14 | 45.9 | 96 | 15 | 46.4 | 97 | 14 | 46.5 | 98 | 14 | 39.4 | 83 | 10
34 | 47.5 | 14 | 46.3 | 98 | 15 | 46.9 | 99 | 14 | 46.4 | 98 | 14 | 40.0 | 84 | 10
35 | 47.0 | 13 | 46.3 | 99 | 15 | 47.2 | 100 | 14 | 46.2 | 98 | 14 | 38.4 | 82 | 9
36 | 47.5 | 13 | 46.7 | 98 | 15 | 46.6 | 98 | 13 | 46.6 | 98 | 14 | 38.3 | 81 | 9
37 | 48.0 | 13 | 46.9 | 98 | 14 | 47.7 | 99 | 13 | 46.7 | 97 | 14 | 37.7 | 79 | 9
38 | 48.6 | 13 | 47.2 | 97 | 14 | 47.8 | 98 | 13 | 47.1 | 97 | 14 | 37.5 | 77 | 9
39 | 48.6 | 13 | 47.5 | 98 | 14 | 48.3 | 99 | 13 | 47.2 | 97 | 14 | 38.7 | 80 | 8
40 | 48.7 | 13 | 47.9 | 98 | 14 | 48.3 | 99 | 13 | 47.5 | 98 | 14 | 38.5 | 79 | 8
Mean for weeks
1-13 | 32.6 | | 32.0 | 98 | | 32.7 | 100 | | 31.8 | 98 | | 30.0 | 93
14-40 | 45.1 | | 43.8 | 97 | | 44.9 | 99 | | 43.4 | 96 | | 36.9 | 82

TABLE 5 Mean Body Weights and Survival of Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg | | | 200 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 21.3 | 15 | 21.5 | 101 | 15 | 21.4 | 101 | 15 | 21.5 | 101 | 15 | 21.6 | 101 | 15
2 | 22.7 | 15 | 22.8 | 100 | 15 | 22.8 | 100 | 15 | 23.0 | 101 | 15 | 23.0 | 101 | 15
3 | 23.5 | 15 | 23.5 | 100 | 15 | 23.7 | 101 | 15 | 23.7 | 101 | 15 | 23.3 | 99 | 15
4 | 24.8 | 15 | 24.8 | 100 | 15 | 24.5 | 99 | 15 | 24.7 | 100 | 15 | 24.7 | 100 | 15
5 | 25.0 | 15 | 24.8 | 99 | 15 | 24.8 | 99 | 15 | 24.7 | 99 | 15 | 24.7 | 99 | 15
6 | 25.0 | 15 | 24.7 | 99 | 15 | 25.0 | 100 | 15 | 24.9 | 100 | 15 | 24.8 | 99 | 15
7 | 26.2 | 15 | 25.7 | 98 | 15 | 26.0 | 99 | 15 | 26.1 | 100 | 15 | 25.1 | 96 | 15
8 | 26.0 | 15 | 25.9 | 100 | 15 | 25.9 | 100 | 15 | 26.0 | 100 | 15 | 25.3 | 97 | 15
9 | 26.2 | 15 | 26.0 | 99 | 15 | 25.7 | 98 | 15 | 25.5 | 97 | 15 | 25.8 | 99 | 15
10 | 27.7 | 15 | 27.1 | 98 | 15 | 26.8 | 97 | 15 | 26.1 | 94 | 15 | 26.5 | 96 | 15
11 | 27.1 | 15 | 26.5 | 98 | 15 | 26.4 | 97 | 15 | 26.1 | 96 | 15 | 25.8 | 95 | 15
12 | 27.2 | 15 | 27.0 | 99 | 15 | 26.8 | 98 | 15 | 26.7 | 98 | 15 | 26.1 | 96 | 15
13 | 28.5 | 14 | 27.6 | 97 | 15 | 27.0 | 95 | 15 | 27.0 | 95 | 15 | 26.9 | 94 | 15
14 | 28.7 | 14 | 27.8 | 97 | 15 | 27.3 | 95 | 15 | 27.3 | 95 | 15 | 26.3 | 92 | 15
15 | 29.4 | 14 | 28.2 | 96 | 15 | 27.8 | 95 | 15 | 27.6 | 94 | 15 | 26.9 | 92 | 15
16 | 30.0 | 14 | 29.0 | 97 | 15 | 28.2 | 94 | 15 | 28.0 | 93 | 15 | 26.6 | 89 | 15
17 | 30.6 | 14 | 28.9 | 94 | 15 | 28.4 | 93 | 15 | 27.9 | 91 | 15 | 27.0 | 88 | 15
18 | 30.5 | 14 | 29.0 | 95 | 15 | 28.4 | 93 | 15 | 28.2 | 93 | 15 | 26.7 | 88 | 15
19 | 30.4 | 14 | 29.3 | 96 | 15 | 29.0 | 95 | 15 | 28.6 | 94 | 15 | 26.6 | 88 | 15
20 | 31.4 | 14 | 30.4 | 97 | 15 | 29.5 | 94 | 15 | 29.5 | 94 | 15 | 27.2 | 87 | 14
21 | 31.9 | 14 | 30.1 | 94 | 15 | 29.4 | 92 | 15 | 29.1 | 91 | 15 | 27.1 | 85 | 14
22 | 33.0 | 14 | 30.8 | 93 | 15 | 30.3 | 92 | 15 | 29.4 | 89 | 15 | 27.9 | 85 | 14
23 | 33.4 | 14 | 30.7 | 92 | 15 | 30.7 | 92 | 15 | 30.3 | 91 | 15 | 27.6 | 83 | 14
24 | 34.1 | 14 | 31.4 | 92 | 15 | 31.6 | 93 | 15 | 30.3 | 89 | 15 | 27.7 | 81 | 14
25 | 33.9 | 14 | 31.5 | 93 | 15 | 31.3 | 92 | 15 | 30.4 | 90 | 15 | 27.6 | 81 | 14
26 | 34.7 | 14 | 32.2 | 93 | 15 | 31.9 | 92 | 15 | 30.6 | 88 | 15 | 28.5 | 82 | 14
27 | 34.8 | 14 | 33.3 | 96 | 15 | 32.4 | 93 | 15 | 30.8 | 89 | 15 | 28.4 | 82 | 14
28 | 36.1 | 14 | 33.7 | 93 | 15 | 33.1 | 92 | 15 | 31.3 | 87 | 15 | 28.1 | 78 | 13
29 | 36.0 | 14 | 33.9 | 94 | 15 | 33.7 | 94 | 15 | 32.0 | 89 | 15 | 28.1 | 78 | 13
30 | 36.6 | 14 | 34.0 | 93 | 15 | 34.6 | 95 | 15 | 32.0 | 87 | 15 | 28.6 | 78 | 13
31 | 38.2 | 14 | 35.8 | 94 | 15 | 35.9 | 94 | 15 | 33.3 | 87 | 15 | 29.6 | 78 | 12
32 | 38.6 | 14 | 35.8 | 93 | 15 | 36.3 | 94 | 15 | 33.2 | 86 | 15 | 29.2 | 76 | 12
33 | 39.4 | 14 | 36.2 | 92 | 15 | 36.6 | 93 | 15 | 33.1 | 84 | 15 | 29.7 | 76 | 12
34 | 39.6 | 14 | 36.4 | 92 | 15 | 37.2 | 94 | 14 | 33.7 | 85 | 15 | 29.9 | 76 | 12
35 | 39.8 | 14 | 36.8 | 93 | 15 | 37.8 | 95 | 13 | 33.7 | 85 | 15 | 29.8 | 75 | 12
36 | 39.2 | 14 | 37.7 | 96 | 14 | 38.3 | 98 | 13 | 34.1 | 87 | 14 | 30.2 | 77 | 11
37 | 39.8 | 14 | 37.9 | 95 | 14 | 38.3 | 96 | 13 | 34.1 | 86 | 14 | 29.7 | 75 | 11
38 | 40.2 | 14 | 38.4 | 96 | 14 | 38.6 | 96 | 13 | 34.3 | 85 | 14 | 31.1 | 77 | 11
39 | 40.9 | 14 | 39.0 | 95 | 14 | 37.1 | 91 | 13 | 34.1 | 83 | 14 | 31.1 | 76 | 11
40 | 41.8 | 13 | 39.4 | 94 | 14 | 36.6 | 88 | 13 | 34.5 | 83 | 14 | 31.2 | 75 | 11
Mean for weeks
1-13 | 25.5 | | 25.2 | 99 | | 25.1 | 99 | | 25.1 | 99 | | 24.9 | 98
14-40 | 35.3 | | 33.2 | 94 | | 33.0 | 94 | | 31.2 | 89 | | 28.5 | 81

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of histiocytic sarcoma and neoplasms and/or nonneoplastic lesions in the lung, forestomach, brain, heart, and thymus. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A1, A2, A3, and A4.

Gross lesions observed at necropsy included enlarged spleen and foci of discoloration in the liver in 200 mg/kg male mice.

Histiocytic sarcoma: Compared to the vehicle control and historical control incidences, the incidences of histiocytic sarcoma were increased in dosed groups of males, and the increases were significant in 50 and 200 mg/kg males (Tables 6, A1, and F1). The incidences of this neoplasm in females administered 50 mg/kg or greater were slightly increased and exceeded the historical control range (Tables 6, A3, and F3). Histiocytic sarcoma involved multiple organs including the bone marrow, heart, kidney, liver, lung, ovary, spleen, and uterus. Histiocytic sarcoma is a malignant neoplasm putatively of macrophage/histiocytic lineage and is considered a systemic neoplasm that can arise from within and spread to various organs. It is a common neoplasm in heterozygous p16^Ink4a^ control mice.

Lung: The incidences of alveolar/bronchiolar adenoma in 100 mg/kg males and 200 mg/kg females were significantly greater than those in the vehicle controls (Tables 7, A1, and A3). The incidences of alveolar/bronchiolar adenoma in 50 mg/kg or greater males and 200 mg/kg females exceeded the historical control ranges (Tables 6, F1, and F3) Two 100 mg/kg males and one 200 mg/kg male had multiple alveolar/bronchiolar adenomas, and one 25 mg/kg male had multiple alveolar/bronchiolar carcinomas. Alveolar/bronchiolar adenomas were well-demarcated, mildly compressing, solid to papillary masses of well-differentiated cuboidal to round cells. Carcinomas were more irregular masses of pleomorphic cells with variable amounts of compression and invasion. One or two animals in most dosed groups and in the female vehicle control group had alveolar epithelial hyperplasia (Tables 7, A2, and A4). Alveolar epithelial hyperplasia consisted of focal thickening of the alveolar septa caused by increased numbers of prominent, cuboidal type-II pneumocytes, with maintenance of normal alveolar septal architecture.

TABLE 6 Incidences of Histiocytic Sarcoma in Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Histiocytic Sarcoma^a,b^
Overall rate^c^ | 2/15 (13%) | 6/15 (40%) | 9/15 (60%) | 5/15 (33%) | 11/15 (73%)
Terminal rate^d^ | 1/13 (8%) | 5/14 (36%) | 7/13 (54%) | 5/14 (36%) | 4/7 (57%)
First incidence (days) | 196 | 253 | 146 | 280 (T) | 181
Statistical analysis^e^ | P=0.005 | P=0.107 | P=0.010 | P=0.195 | P<0.001
Female
Histiocytic Sarcoma^f^
Overall rate | 9/15 (60%) | 9/15 (60%) | 12/15 (80%) | 10/15 (67%) | 13/15 (87%)
Terminal rate | 8/13 (62%) | 8/14 (57%) | 9/12 (75%) | 9/14 (64%) | 8/9 (89%)
First incidence (days) | 267 | 239 | 232 | 239 | 133
Statistical analysis | P=0.076 | P=0.645N | P=0.213 | P=0.500 | P=0.107

(T) Terminal sacrifice

a Histiocytic sarcoma involved multiple organs including the liver, bone marrow, ovary, spleen, heart, lung, kidney, and uterus.

b Historical incidence for 40-week studies with haploinsufficient p16^Ink4a^/p19^Arf^ mouse vehicle control groups: 4/30 (13%), range 13%

c Number of animals with neoplasm per number of animals necropsied

d Observed incidence at terminal kill

e The result of the Cochran-Armitage trend test (Armitage, 1971) is in the vehicle control column, and the results of the Fisher exact pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A lower incidence in a dosed group is indicated by N.

f Historical incidence: 14/30 (47%), range 33%-60%

TABLE 7 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Number Examined Microscopically | 15 | 15 | 15 | 15 | 15
Alveolar Epithelium, Hyperplasia, Focal^a^ | 0 | 2 (1.0)^b^ | 0 | 2 (1.0) | 2 (1.5)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 0 | 0 | 2 | 1
Alveolar/bronchiolar Adenoma (includes multiple)^c^
Overall rate^c^ | 1/15 (7%) | 0/15 (0%) | 2/15 (13%) | 7/15 (47%) | 3/15 (20%)
Terminal rate^e^ | 1/13 (8%) | 0/14 (0%) | 2/13 (15%) | 7/14 (50%) | 3/7 (43%)
First incidence (days) | 280 (T) | —^g^ | 280 (T) | 280 (T) | 280 (T)
Statistical analysis^f^ | P=0.053 | P=0.500N | P=0.500 | P=0.018 | P=0.299
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 1 | 0 | 0 | 0
Alveolar/bronchiolar Carcinoma (includes multiple)^h^
Overall rate | 2/15 (13%) | 1/15 (7%) | 1/15 (7%) | 3/15 (20%) | 0/15 (0%)
Terminal rate | 2/13 (15%) | 1/14 (7%) | 1/13 (8%) | 3/14 (21%) | 0/7 (0%)
First incidence (days) | 280 (T) | 280 (T) | 280 (T) | 280 (T) | —
Statistical analysis | P=0.287N | P=0.500N | P=0.500N | P=0.500 | P=0.241N
Alveolar/bronchiolar Adenoma or Carcinoma^i^
Overall rate | 3/15 (20%) | 1/15 (7%) | 3/15 (20%) | 8/15 (53%) | 3/15 (20%)
Terminal rate | 3/13 (23%) | 1/14 (7%) | 3/13 (23%) | 8/14 (57%) | 3/7 (43%)
First incidence (days) | 280 (T) | 280 (T) | 280 (T) | 280 (T) | 280 (T)
Statistical analysis | P=0.252 | P=0.299N | P=0.674N | P=0.064 | P=0.674N
Female
Number Examined Microscopically | 15 | 15 | 15 | 15 | 15
Alveolar Epithelium, Hyperplasia, Focal | 1 (4.0) | 2 (3.0) | 1 (3.0) | 0 | 2 (1.0)
Alveolar/bronchiolar Adenoma^c^
Overall rate | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 1/15 (7%) | 4/15 (27%)
Terminal rate | 0/13 (0%) | 1/14 (7%) | 0/12 (0%) | 1/14 (7%) | 2/9 (22%)
First incidence (days) | — | 281 (T) | — | 281 (T) | 208
Statistical analysis | P=0.005 | P=0.500 | —^j^ | P=0.500 | P=0.050
Alveolar/bronchiolar Carcinoma^k^
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%)
Terminal rate | 0/13 (0%) | 0/14 (0%) | 0/12 (0%) | 1/14 (7%) | 0/9 (0%)
First incidence (days) | — | — | — | 281 (T) | —
Statistical analysis | P=0.639 | — | — | P=0.500 | —
Alveolar/bronchiolar Adenoma or Carcinoma^c^
Overall rate | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 2/15 (13%) | 4/15 (27%)
Terminal rate | 0/13 (0%) | 1/14 (7%) | 0/12 (0%) | 2/14 (14%) | 2/9 (22%)
First incidence (days) | — | 281 (T) | — | 281 (T) | 208
Statistical analysis | P=0.006 | P=0.500 | — | P=0.241 | P=0.050

(T) Terminal sacrifice

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

c Historical incidence for 40-week studies with haploinsufficient p16^Ink4a^/p19^Arf^ mouse studies with vehicle control groups: 1/30 (3%), range 0%-7%

d Number of animals with neoplasm per number of animals with lung examined microscopically

e Observed incidence at terminal kill

f The result of the Cochran-Armitage trend test (Armitage, 1971) is in the vehicle control column, and the results of the Fisher exact pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A lower incidence in a dosed group is indicated by N.

g Not applicable; no neoplasms in animal group

h Historical incidence: 2/30 (7%), range 0%-13%

i Historical incidence: 3/30 (10%), range 0%-20%

j Value of statistic cannot be computed

k Historical incidence: 0/30 (0%)

Forestomach: One 200 mg/kg male, one 100 mg/kg female, and three 200 mg/kg females had squamous cell papillomas (Tables 8, A1, and A3). In male and female mice administered 200 mg/kg, the incidences of epithelial hyperplasia were significantly greater than those in the vehicle controls, and the severities were slightly increased in males (Tables 8, A2, and A4). Squamous cell papillomas consisted of small papillary projections of well-differentiated squamous epithelium overlying a thin lamina propria and protruding into the gastric lumen. Epithelial hyperplasia consisted of focal, poorly demarcated thickening of the stratified squamous epithelium due to increased numbers of well-differentiated squamous cells. Occasionally, the hyperplasia caused small convolutions. The incidence of ulcer was increased in male mice administered 200 mg/kg.

TABLE 8 Incidences of Neoplasms and Nonneoplastic Lesions of the Forestomach in Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Number Necropsied | 15 | 15 | 15 | 15 | 15
Epithelium, Hyperplasia^a^ | 0 | 1 (2.0)^b^ | 1 (2.0) | 0 | 6^**^ (2.5)
Ulcer | 0 | 1 (2.0) | 0 | 0 | 3 (1.7)
Squamous Cell Papilloma, Multiple
Overall rate_d_ | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%)
Terminal rate^d^ | 0/13 (0%) | 0/14 (0%) | 0/13 (0%) | 0/14 (0%) | 0/7 (0%)
First incidence (days) | —^f^ | — | — | — | 218
Statistical analysis^e^ | P=0.143 | —^g^ | — | — | P=0.500
Female
Number Necropsied | 15 | 15 | 15 | 15 | 15
Epithelium, Hyperplasia | 0 | 0 | 0 | 1 (1.0) | 4^*^ (1.3)
Squamous Cell Papilloma
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 3/15 (20%)
Terminal rate | 0/13 (0%) | 0/14 (0%) | 0/12 (0%) | 1/14 (7%) | 1/9 (11%)
First incidence (days) | — | — | — | 281 (T) | 278
Statistical analysis | P=0.005 | — | — | P=0.500 | P=0.112

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

(T) Terminal sacrifice

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

c Number of animals with neoplasm per number of animals necropsied

d Observed incidence at terminal kill

e The result of the Cochran-Armitage trend test (Armitage, 1971) is in the vehicle control column, and the results of the Fisher exact pairwise _f_ comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed

Brain: Neuronopathy occurred in 33% of the 200 mg/kg males and 7% and 27% of the 100 mg/kg and 200 mg/kg females, respectively (Table 9). Neuronopathy was a chronic, ongoing process that ranged from minimal to severe, depending on the location in the brain. Neuronopathy was present in the cerebrum, cerebellum, medulla, hippocampus, and/or thalamus and was accompanied by minimal to mild gliosis and hemorrhage. More specifically, neuronopathy involved the red, cerebellar roof, vestibular, and/or oculomotor nuclei. Histologically, the neuronopathy consisted of a localized minimal to marked loss of neurons resulting in vacuolization ex vacuo (Plates 1 and 2). Lesions were those of symmetric and asymmetric areas of shrunken or vacuolated neurons and/or glial cells, as well as clear spaces where neuronal cell bodies and processes would have been found normally. Symmetrical lesions were generally found in specific regions of the brain such as nuclei of the cerebellum, medulla, and/or midbrain that included the red nucleus and thalamic/hypothalamic nuclei. Nuclei most often affected were the red nucleus and cerebellar roof nuclei. Asymmetric lesions were generally found in the cerebrum or hippocampus. Some neurons had one or more small vacuoles, but generally, remaining neurons were morphologically normal. The neuropil was relatively unremarkable except for rare examples of swollen axons.

TABLE 9 Incidences of Nonneoplastic Lesions of the Brain in Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Number Examined Microscopically | 15 | 15 | 15 | 15 | 15
Neuronopathy^a^ | 0 | 0 | 0 | 0 | 5^*^ (2.2)^b^
Gliosis | 0 | 0 | 0 | 0 | 4^*^ (1.2)
Hemorrhage | 0 | 0 | 0 | 0 | 2 (2.7)
Female
Number Examined Microscopically | 15 | 15 | 15 | 15 | 15
Neuronopathy | 0 | 0 | 0 | 1 (1.0) | 4^*^ (2.7)
Gliosis | 0 | 0 | 0 | 0 | 4^*^ (1.5)
Hemorrhage | 0 | 0 | 0 | 1 (1.0) | 0

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test.

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

The five males and two of four females with neuronopathy died before the end of the study. All five males and three of four females diagnosed with neuronopathy had clinical signs of tremors, ataxia, ruffled fur, abnormal breathing, thinness, and/or lethargy just prior to euthanasia or natural death. All of the mice with neuronopathy had histiocytic sarcoma often involving major organs such as brain, heart, lung, and kidney. The mortality and extensive disseminated histiocytic sarcoma in these mice suggest that multiorgan impairment or failure may have contributed to morbidity.

Heart: The incidence of myocardial mineralization in 200 mg/kg males was significantly greater than that in the vehicle controls (0/15, 0/15, 2/15, 1/15, 5/15; Table A2). All 200 mg/kg males with this lesion died before the end of the study.

Thymus: The incidences of atrophy in 200 mg/kg males and in 25, 100, and 200 mg/kg females were greater than those in the vehicle controls (males: 2/15, 0/15, 1/15, 0/15, 4/15; females: 0/15, 2/15, 0/15, 1/15, and 3/15; Tables A2 and A4).

## Genetic Toxicology

The frequency of micronucleated erythrocytes was monitored in peripheral blood of male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice from the 40-week study. No significant increases were observed at the 6.5, 13, or 19.5 week sampling times (Table B1). At 6.5 weeks, elevations in the frequencies of micronucleated normochromatic erythrocytes (NCEs) were observed in female mice in the 50 and 100 mg/kg groups. However, because the trend test was not significant and the increases were small (less than twice the vehicle control frequency), the results were judged to be negative. Similarly, male mice sampled at 19.5 weeks showed a small increase in micronucleated NCEs at the high dose (200 mg/kg), but the increase was not statistically different from the vehicle control value. Therefore, despite the positive trend (P=0.002), the test was judged to be negative. In male and female mice sampled at 26 and 40 weeks of treatment, small but statistically significant increases were seen in the frequencies of micronucleated NCEs. Based on positive trend and pairwise analyses, results in male and female mice at these two time points were judged to be positive. In addition to micronucleus frequencies, the percentage of polychromatic erythrocytes (PCEs) in total erythrocytes was measured in mice at each time point; no changes with dose or time were noted until the final sample at 40 weeks. At 40 weeks, the percentage of PCEs in male mice was slightly higher than the percentages noted at earlier sampling times, and there were small but nonsignificant increases in percentages of PCEs at the two middle doses of 50 and 100 mg/kg. The percentage of PCEs in vehicle control females was also increased over the percentages noted at earlier sample times, and the percentages in the 50 and 100 mg/kg groups were significantly increased.

PLATE 1 Bilaterally symmetrical neuronopathy affecting the thalamus (arrows) in a female haploinsufficient p16^Ink4a^/p19^Arf^ mouse treated with 200 mg/kg glycidol by gavage for 40 weeks

PLATE 2 Higher magnification of Plate 1 showing typical features of neuronopathy such as vacuolated neurons and glial cells (large arrows), shrunken neurons (small arrows), and pyknotic cell debris (arrowhead)