# MATERIALS AND METHODS

## Procurement and Characterization of Glycidol

Glycidol was obtained from Aldrich Chemical Co. (Milwaukee, WI) in one lot (01616 BS) and was used in the 40-week study. Identity and purity analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC), and the study laboratory, Battelle Columbus Operations (Columbus, OH); stability analyses were also conducted by the analytical chemistry laboratory (Appendix E). Reports on analyses performed in support of the glycidol studies are on file at the National Institute of Environmental Health Sciences.

Lot 01616 BS of the chemical, a viscous, colorless, combustible liquid (NTP, 2004), was identified as glycidol using infrared spectroscopy and proton nuclear magnetic resonance (NMR) spectroscopy by the analytical chemistry laboratory and infrared spectroscopy by the study laboratory. Spectra were consistent with the structure of glycidol, matched reference spectra (Aldrich, 1981, 1983, 1985), and matched the spectrum of a reference standard from the same lot.

The purity of lot 01616 BS was determined by the analytical chemistry and study laboratories using gas chromatography (GC). GC by the analytical chemistry laboratory indicated one major peak, six impurities with peak areas greater than 0.1% of the total peak area, ranging from 0.12% to 1.18%, and seven impurities with peak areas less than 0.1% of the total peak area; the purity of lot 01616 BS was determined to be greater than 96%. Impurities were identified by GC mass spectrometry and quantitated using GC flame ionization detection. Impurities with peak areas exceeding 0.1% were 1-hydroxy-2-propanone (0.6%), diglycidyl ether (0.3%), 3-methoxy-1,2-propanediol (0.5%), 2,5-dimethanol-p-dioxane (0.1%), 2,6-dimethanol-pdioxane (2.2%), and glycidol-dimethyl ether (0.2%). GC by the study laboratory indicated one major peak and several minor impurities; the purity was determined to be 95.9% by comparison to a reference standard from the same lot. The overall purity of lot 01616 BS was determined to be greater than 95%.

Analyses of the bulk chemical were performed by the study laboratory at approximately 2 and 8 months and at the end of the study using GC. To ensure stability, the bulk chemical was protected from light in amber glass bottles capped with Teflon^®^-lined lids and stored at approximately 5° C. No degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared monthly. The dose formulations were prepared by mixing the appropriate amount of glycidol with deionized water to give the required concentrations (Table E1). Formulations were protected from light in amber glass bottles capped with Teflon^®^-lined lids and stored at approximately 5° C for up to 35 days.

The study laboratory conducted periodic analyses of preadministration dose formulations five times during the study using GC; postadministration formulations were also analyzed. All of the preadministration dose formulations used and analyzed were within 10% of the target concentrations; of the postadministration formulations analyzed, all 16 were more than 10% less than the target concentrations, ranging from −11% to −17%, probably due to the evaporation of glycidol during administration (Table E2).

## 40-Week Study

### Study Design

Groups of 15 male and 15 female mice received glycidol in deionized water by gavage at doses of 0, 25, 50, 100, or 200 mg glycidol/kg body weight 5 days per week for 40 weeks. A p53^+/–^ mouse study was reported to be negative when glycidol was administered by gavage at 0, 25, or 50 mg/kg body weight for 6 months (Tennant et al., 1999). Thus, doses for the 40-week glycidol study in haploinsufficient p16^Ink4a^/p19^Arf^ mice were selected to overlap those in the p53^+/–^ mouse glycidol study (Tennant et al., 1999) and the NTP (1990) 2-year gavage study in B6C3F_1_ mice (0, 25, or 50 mg/kg) and include higher doses to test the model over a broader dose range. A 40-week dosing period was selected (rather than a 27-week dosing period) to allow for more time for cancer development (ILSI, 2001).

### Source and Specification of Animals

Male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice developed by Serrano et al. (1996) were obtained from Taconic Laboratory Animals and Services (Germantown, NY). To produce the mice used in these studies, the N1 male mouse homozygous null for the Cdkn2a deletion (Serrano et al., 1996) was backcrossed to inbred C57BL/6 female mice from Taconic to produce male and female B6.129-Cdkn2^atm1Rdp^ haploinsufficient or haploinsufficient p16^Ink4a^/p19^Arf^ mice. The genetic background of these mice was 80% C57BL/6, 19% 129/Sv, and 1% SJL. This line, designated 5003 by Taconic, was embryo cryopreserved in 2003. On receipt, the mice were 4 to 5 weeks old. Animals were quarantined for 28 days and were 8 to 9 weeks old on the first day of the study. Before the study began, five male and five female mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood samples were collected from up to five male and five female sentinel animals at 1, 4, and 6 months and at study termination. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative.

### Animal Maintenance

Feed and water were available ad libitum. Mice were housed individually. Clinical findings were recorded weekly, to coincide with body weight collection, and at the end of the study. The animals were weighed initially, weekly, and at the end of the study. Details of the study design and animal maintenance are summarized in Table 2.

### Clinical Examinations and Pathology

At the end of the 40-week study, samples were collected for sperm motility evaluations on all male mice. The parameters evaluated are listed in Table 2. For sperm count and motility, the left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Modified Tyrode’s buffer was applied to slides, and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65° C. Sperm density was then determined microscopically with the aid of a hemacytometer. Four sperm morphology slides were prepared for each animal evaluated. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all animals. The heart, right kidney, liver, lungs, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. An extended evaluation of the brain (five sections per animal) was conducted in all mice. Histopathologic examinations were performed on all mice. Table 2 lists the tissues and organs routinely examined.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified, and the histotechnique was evaluated. For the 40-week study, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included brain, forestomach, liver, and lung.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) chairperson, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the chairperson to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

TABLE 2 Experimental Design and Materials and Methods in the Gavage Study of Glycidol

Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Haploinsufficient p16^Ink4a^/p19^Arf^ mice
Animal Source
Taconic Laboratory Animals and Services (Germantown, NY)
Time Held Before Study
28 days
Average Age When Studies Began
8 to 9 weeks
Date of First Dose
February 3, 2000
Duration of Dosing
5 days/week for 40 weeks
Date of Last Dose
November 7-9, 2000
Necropsy Dates
November 8-10, 2000
Average Age at Necropsy
48 to 49 weeks
Size of Study Groups
15 males and 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo and ear tags
Diet
Irradiated NTP-2000 pelleted feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages and Racks
Polycarbonate cages in stainless steel racks (Lab Products Corp., Seaford, DE), changed weekly
Bedding
Irradiated Sani-Chips^®^ (PJ. Murphy Forest Products Corp., Montville, NJ), changed weekly
Cage Filters
DuPont 2024 spun-bonded polyester (Snow Filtration Co., Cincinnati, OH)
Animal Room Environment
Temperature: 72° ± 3° F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: 10/hour
Doses
0, 25, 50, 100, or 200 mg/kg in water (dosing volume 10 mL/kg body weight)
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, weekly, and at the end of the study; clinical findings were recorded weekly.
Method of Sacrifice
CO_2_ asphyxiation
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lungs, right testis, and thymus.
Histopathology
Histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow (femur and sternum), brain, large intestine (colon and cecum), small intestine (duodenum, ileum, jejunum), heart, kidney, liver, lung, lymph nodes (mandibular, mesenteric), mammary gland, ovary, pituitary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, urinary bladder, and uterus.
Sperm Motility
At the end of the study, sperm samples were collected from all male mice for sperm motility evaluations. Spermatid and sperm measurements were evaluated. The left cauda, left epididymis, and left testis were weighed.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958). Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation and Analysis of Lesion Incidences

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A2, A3, and A4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979) and the Cochran-Armitage trend test (Armitage, 1971; Gart et al., 1979), procedures based on the overall proportion of affected animals, were used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Spermatid and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) (as modified by Williams, 1986) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1957) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973). Treatment effects were investigated by applying a multivariate analysis of variance (Morrison, 1976) to the transformed data to test for simultaneous equality of measurements across dose concentrations.

## Quality Assurance Methods

The 40-week study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records were submitted to the NTP Archives, this study was audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Mouse Peripheral Blood Micronucleus Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). Blood samples were obtained from male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice, and smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were sent to the genetic toxicity testing laboratory (SITEK Research Laboratories, Inc.), stained with acridine orange, and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) per animal per dose group. In addition, the percentage of polychromatic erythrocytes among 1,000 total erythrocytes was determined for each animal as a measure of glycidol-induced bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dose group and the vehicle control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.