# INTRODUCTION

GLYCIDOL

CAS No. 556-52-5

Chemical Formula: C_3_H_6_O_2_ Molecular Weight: 74.08

Synonyms: Allyl alcohol oxide; epihydrin alcohol; 1,2-epoxy-3-hydroxypropane; 2,3-epoxypropanol; 2,3-epoxy-1-propanol; epoxypropyl alcohol; glycide; glycidyl alcohol; 1-hydroxy-2,3-epoxypropane; 3-hydroxy-1,2-epoxypropane; 3-hydroxyl-1,2-epoxypropane; hydroxymethyl ethylene oxide; 2-(hydroxymethyl)oxirane; 2-hydroxymethyloxiran; oxiranemethanol; oxiranylmethanol; 1-propanol, 2,3-epoxy-methanol

## Chemical and Physical Properties

Glycidol is a viscous, colorless liquid that boils at 160° C (HSDB, 2006). It is soluble in water, alcohol, ether, acetone, benzene, and other organic solvents. At 25° C, the vapor pressure is 0.9 mm mercury. Glycidol is combustible with a flash point of 72° C and is incompatible with strong oxidizers and nitrates. It explodes when heated or in the presence of strong acids, bases, metals, and metal salts (NTP, 2004; HSDB, 2006).

## Production, Use, and Human Exposure

Glycidol is used as a chemical intermediate in the pharmaceutical industry, as a stabilizer in the manufacture of vinyl polymers, and as an intermediate in the synthesis of glycerol, glycidyl ethers, and amines. Glycidol is also used as an additive for oil and synthetic hydraulic fluids, as a diluent in some epoxy resins, and as a dye-leveling agent. One domestic producer and 18 suppliers of glycidol were reported in 2000. No recent production data were found. In the past, more than 10 million pounds of glycidol compounds were produced or imported annually into the United States (NTP, 2004).

The primary routes of potential human exposures to glycidol are inhalation, eye or dermal contact, and ingestion. Occupational exposure may occur through inhalation (NTP, 2004). The National Occupational Exposure Survey conducted by the National Institute for Occupational Safety and Health (1990) from 1981 to 1983 estimated that 4,871 workers, at 88 facilities and in 10 occupations, were potentially exposed to glycidol. This estimate was derived from observations of the actual use of the compound (78% of total observations) and the use of trade name products known to contain the compound.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Figure 1 shows the known and proposed metabolic reactions of glycidol. Because of the reactivity of epoxides, in solution glycidol can undergo several spontaneous reactions involving nucleophilic attack at the α or β carbon (March, 1978); at neutral pH and 37° C, glycidol slowly hydrolyzes to glycerol; in 0.1 M hydrochloric acid, the hydrolysis to glycerol (97.2%) and α-chlorohydrin (3-chloro-1,2-propanediol) (2.8%) occurs rapidly, with a half-life of 10 minutes. At pH 6, glycidol does not readily react with glutathione; however, at pH 7 or 8, the reaction to form S-(2,3-dihydroxypropyl)glutathione occurs readily. Glycidol may also directly alkylate various cellular components (Jones, 1975).

The major urinary metabolites isolated from rats administered glycidol by intraperitoneal injection are S-(2,3-dihydroxypropyl)glutathione, S-(2,3-dihydroxypropyl)cysteine, and β-chlorolactic acid. The latter compound was identified as the only radioactive urinary metabolite of glycidol isolated from rats administered [^36^Cl]saline for 3 days before glycidol administration (Jones and O’Brien, 1980). The same urinary metabolites are found after α-chlorohydrin administration, suggesting that glycidol is converted to α-chlorohydrin by direct reaction with hydrochloric acid in the stomach. α-Chlorohydrin may then be converted to the glutathione metabolite by the action of glutathione transferase or oxidized to α-chlorolactate by the successive action of alcohol dehydrogenase and aldehyde dehydrogenase. The conversion of glycidol to glycerol by epoxide hydrase has been observed with rat liver microsomal preparations (Patel et al., 1980). The oxidation of glycidol to glycidaldehyde has not been observed, but glycidaldehyde is a potential metabolite formed by the action of alcohol dehydrogenase.

### Humans

No studies on the absorption, distribution, metabolism, or excretion of glycidol in humans were found in a review of the literature.

## Toxicity

### Experimental Animals

The NTP (1990) conducted toxicity studies of glycidol in F344/N rats and B6C3F_1_ mice in which the chemical was administered by oral gavage (5 days per week) at doses of 0, 37.5, 75, 150, 300, or 600 mg/kg for 16 days. All rats that received 600 mg/kg died between days 3 and 13 of the study. Edema and degeneration of the epididymal stroma, atrophy of the testis, and granulomatous inflammation of the epididymis occurred in males that received 300 mg/kg. All mice that received 600 mg/kg and three males and two females that received 300 mg/kg died by day 4 of the study. Focal demyelination in the medulla and thalamus of the brain occurred in all female mice that received 300 mg/kg.

In 13-week studies, F344/N rats received glycidol by oral gavage (5 days/week) at doses of 0, 25, 50, 100, 200, or 400 mg/kg and B6C3F_1_ mice received doses of 0, 19, 38, 75, 150, or 300 mg/kg (NTP, 1990). All rats that received 400 mg/kg died by week 2; three males and one female that received 200 mg/kg died during weeks 11 and 12. Final mean body weights of male rats that received 50, 100, or 200 mg/kg were 85% to 96% that of vehicle controls; final mean body weights of female rats receiving the same doses were 89% to 94% that of vehicle controls. Necrosis of the cerebellum occurred in rats administered 200 or 400 mg/kg, and demyelination in the medulla of the brain, tubular degeneration and/or necrosis of the kidney, and lymphoid necrosis of the thymus occurred in rats that received 400 mg/kg. Testicular atrophy occurred in male rats administered 200 or 400 mg/kg. All mice that received 300 mg/kg died by week 2; four of 10 males and three of 10 females that received 150 mg/kg died. Mean body weights of 19, 38, 75, and 150 mg/kg males and all dosed groups of female mice surviving to the end of the studies were generally 90% to 94% those of vehicle controls. Compound-related histopathologic lesions included demyelination of the brain in male and female mice that received 150 or 300 mg/kg. Testicular atrophy was observed in male mice at all doses, and renal tubular cell degeneration was observed in male mice that received 300 mg/kg.

### Humans

No toxicity studies of glycidol in humans were found in a review of the literature.

## Reproductive Toxicity

### Experimental Animals

In the 13-week studies (NTP, 1990), sperm count and sperm motility were reduced in male F344/N rats that received 25, 100, or 200 mg/kg, and sperm counts and sperm motility were reduced in B6C3F_1_ mice that received 75 or 150 mg/kg. Glycidol did not affect the reproductive patterns of female rats or mice (NTP, 1990; Bishop et al., 1997). In a review of the literature, the NTP reported that glycidol was teratogenic in some species of rats (Slott and Hales, 1985).

FIGURE 1 Metabolic Pathways for Glycidol (March, 1978)

### Humans

No studies of reproductive toxicity of glycidol in humans were found in a review of the literature.

## Carcinogenicity

### Experimental Animals

In a 2-year oral gavage study (5 days per week in corn oil) in F344/N rats and B6C3F_1_ mice, glycidol was carcinogenic in several target organs (Table 1; NTP, 1990).

Glycidol did not induce skin tumors in ICR/Ha Swiss mice when the chemical was administered by skin painting three times per week for 520 days at a concentration of 5% in acetone (IARC, 2000). Glycidol did not induce tumors in Syrian golden hamsters when administered at approximately 100 mg/kg body weight twice a week for 60 weeks (IARC, 2000). Glycidol did not cause a carcinogenic effect in a 6-month p53^+/−^ mouse study (Tennant et al., 1999).

### Humans

Glycidol is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity in experimental animals (NTP, 1990, 2004; IARC, 2000). No adequate exposure studies on the relationship between glycidol and cancer in humans have been reported (NTP, 2004).

## Genetic Toxicity

Glycidol is a demonstrated potent genotoxin, in vitro and in vivo. Its mutagenicity has been reviewed by The International Agency for Research on Cancer (2000). Glycidol has been shown to induce large numbers of gene mutations in several strains of Salmonella typhimurium with and without liver S9 activation enzymes (Canter et al., 1986), and it induced increases in chromosomal aberrations and sister chromatid exchanges in cultured Chinese hamster ovary cells (NTP, 1990). Elevated frequencies of chromosomal aberrations and sister chromatid exchanges were also observed in human lymphocytes treated with glycidol in the absence of S9 (Norppa et al., 1981). Positive results were reported with glycidol in a mammalian cell gene mutation assay using mouse lymphoma L5178Y/tk^+/−^ cells and conducted without S9 activation enzymes (NTP, 1990).

In vivo, glycidol was one of only a few chemicals shown to induce reciprocal translocations in male germ cells of Drosophila melanogaster, and it also induced sex-linked recessive lethal mutations in male Drosophila germ cells (Foureman et al., 1994). Glycidol (150 mg/kg) induced micronuclei in bone marrow erythrocytes of male B6C3F_1_ mice after two intraperitoneal injections (NTP, 1990). In addition, chromosomal aberrations were induced in bone marrow cells of male and female Wistar rats following intraperitoneal injection of glycidol (Thompson and Gibson, 1984).

## Background on Genetically Altered Mice

The CDKN2A genetic locus contains two important tumor suppressor genes located on chromosome 9, 4, and 5 in the human, mouse, and rat, respectively (NCBI, 2005). The locus is unique in that alternate splice variants produce two different tumor suppressor proteins (Sherr and Weber, 2000; Sherr and McCormick, 2002; Lowe and Sherr, 2003). The p16^Ink4a^ and p19^Arf^ variants have exons 2 and 3 in common, but use different exon 1 (alpha and beta). Expression of these two splice variants is conserved across mammalian species. Mouse p19^Arf^ and human p14^Arf^ polypeptides are approximately 50% identical, and mouse p16^Ink4a^ and human p16^Ink4a^ proteins are approximately 72% identical (Quelle et al., 1995).

The two proteins translated from the mRNA expressed from CDKN2A are a p16-KDa protein and a p19-KDa protein (or p14-KDa protein in humans) (Serrano et al., 1996). The p16 protein (p16^Ink4a^, inhibitor of kinase 4a) is a cell cycle regulatory protein that binds to cyclin dependent kinase 4 or 6 (CDK4/6) and inhibits the catalytic activity of the CDK/cyclin D complex and the phosphorylation of retinoblastoma protein. Since loss of the normal function of p16^Ink4a^ leads to uncontrolled cell growth, p16 is classified as a tumor suppressor gene (Serrano et al., 1993). The second protein coded, p19^Arf^ (Arf, alternate reading frame), induces G1 arrest and apoptosis. The 19Arf protein binds to MDM2 and neutralizes MDM2 inhibition of p53 (Sherr and Weber, 2000).

TABLE 1 Organs with Neoplasms in F344/N Rats and B6C3F_1_ Mice Administered Glycidol for 2 Years^a^

Site/Neoplasm^b^ | Male | | | Female
Site/Neoplasm^b^ | Vehicle Control | 37.5 mg/kg | 75 mg/kg | Vehicle Control | 37.5 mg/kg | 75 mg/kg
Rats
Tunica Vaginalis/Peritoneum
Mesothelioma | 3/49 | 34/50 | 39/47
Mammary Gland
Fibroadenoma | 3/45 | 8/39 | 7/17 | 14/49 | 32/46 | 29/44
Adenocarcinoma | | | | 1/50 | 11/48 | 16/48
Brain
Glioma | 0/46 | 5/50 | 6/30 | 0/49 | 4/46 | 4/46
Oral Mucosa
Papilloma or Carcinoma | | | | 1/46 | 3/37 | 7/26
Forestomach
Papilloma or Carcinoma | 1/46 | 2/50 | 6/32 | 0/47 | 4/38 | 11/30
Intestine
Adenomatous Polyp or Adenocarcinoma | 0/47 | 1/50 | 4/37
Skin
Sebaceous Gland Adenoma, Basal Cell Tumor, or Sebaceous Gland Adenocarcinoma | 0/45 | 5/41 | 4/18
Zymbal’s Gland
Carcinoma | 1/49 | 3/50 | 6/48
Clitoral Gland
Adenoma, Adenocarcinoma, or Carcinoma | | | | 5/49 | 9/47 | 12/45
Thyroid Gland
Follicular Cell Adenoma or Carcinoma | 1/46 | 4/42 | 6/19 | 0/49 | 1/38 | 3/35
Hematopoietic System
Leukemia | | | | 13/49 | 14/44 | 20/41

Site/Neoplasm | Male | | | Female
Site/Neoplasm | Vehicle Control | 25 mg/kg | 50 mg/kg | Vehicle Control | 25 mg/kg | 50 mg/kg
Mice
Harderian Gland^c^
Adenoma or Adenocarcinoma | 8/46 | 12/41 | 22/44 | 4/46 | 11/43 | 17/43
Mammary Gland
Adenoma, Fibroadenoma, or Carcinoma | | | | 2/50 | 6/50 | 15/50
Forestomach
Squamous Cell Papilloma or Carcinoma | 1/50 | 2/50 | 10/50
Uterus
Carcinoma or Adenocarcinoma | | | | 0/50 | 3/50 | 3/50
Subcutaneous Tissue
Sarcoma or Fibrosarcoma | | | | 0/50 | 3/50 | 9/50
Skin
Squamous Cell Papilloma or Carcinoma | 0/50 | 0/50 | 4/50 | 0/50 | 0/50 | 2/50
Liver
Adenoma or Carcinoma | 24/50 | 31/50 | 35/50
Lung
Alveolar/bronchiolar Adenoma or Carcinoma | 13/50 | 11/50 | 21/50

a NTP, 1990

b A blank space indicates that the neoplasm incidence at that site and in that sex was not increased by the administration of glycidol. Neoplasm incidence is expressed as the number of neoplasm-bearing animals divided by the number of animals in each group surviving to the time the first neoplasm was observed in any of the three groups.

c The denominators for the incidence of harderian gland neoplasms are the actual number of harderian glands available for microscopic examination.

The targeted deletion of exons 2 and 3 of the Cdkn2a gene by a homologous recombination resulted in the elimination of both p16^Ink4a^ and p19^Arf^ proteins (Serrano et al., 1996). Homozygous null Cdkn2a^–/–^ (or Cdkn2a^–/–^) mice are viable and fertile (Serrano et al., 1996). On inspection, these animals appear normal until about 2 months of age, but histological analysis of the spleen shows a mild proliferative expansion of the white pulp and the presence of numerous megakaryocytes and lymphoblasts in the red pulp. The p16^–/–^ mice develop tumors at an average age of 29 weeks. Lymphomas and fibrosarcomas are two common types of tumors seen in this Cdkn2a^–/–^ mouse. In contrast, the Cdkn2a^+/–^ mouse does not usually develop any obvious tumors or display compromised health until after 36 weeks (Serrano et al., 1996).

Deletions in the Cdkn2a gene predispose both rodents and humans to cancer of multiple organ sites (Sharpless and DePinho, 1999). The complete loss of Cdkn2a gene(s) function is observed in approximately 10% of small cell lung tumors, 30% of esophageal tumors, 55% of gliomas, 100% of pancreatic tumors, and 20% of head and neck tumors (Sharpless and DePinho, 1999).

Transition from G1 to S phase in the mammalian cell cycle is under complex regulatory control, and one G1-S regulatory pathway involves p16^Ink4a^ protein. P16^Ink4a^ inhibits the cdk4/cyclin D1 complex, preventing cdk4 from phosphorylating pRb, and thus ensures that pRb maintains G1 arrest. Disruption of this pathway, by p16^Ink4a^ gene mutations, perturbs the cell cycle (Serrano et al., 1993), and in the case of these Cdkn2a genetically altered mice (Serrano et al., 1993), results in more cell proliferation (Figure 2).

Serrano et al. (1996) report that treatment with DMBA and UV light causes an earlier onset of fibrosarcoma and lymphoma in the p16^–/–^ mouse (8 to 10 weeks) and in the p16^–/+^ mouse (7 to 20 weeks).

## Study Rationale

The purpose of this study of glycidol and the companion studies of benzene and phenolphthalein (NTP, 2007a,b) was to determine if a mouse with a deletion at the p16 gene locus (CDKN2), a locus that codes for two tumor suppressor genes, would enable the identification of carcinogenic chemicals in a shorter time frame and with fewer animals than the traditional 2-year NTP cancer study. These three chemicals were all multisite carcinogens in the NTP 2-year bioassay (NTP 1986, 1990, 1996). This Report presents the findings from the glycidol study.

FIGURE 2 The INK4a/ARF Locus

The open reading frames p16^INK4a^ (in black) and p19^ARF^ (in crosshatch) are shown. Each has a unique first exon that then splices to a common second exon, but in alternate reading frames. P16^INK4a^ inhibits cdk4/6 activity producing retinoblastoma phosphorylation, which induces cell cycle arrest. P19^ARF^ inhibits MDM2-mediated degradation of p53 (Sharpless, 2005).