# APPENDIX F HISTORICAL CONTROL INCIDENCES

TABLE F1 Historical Incidences of Neoplasms in Control Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice^a^

| Benzene | Phenolphthalein | Total
27 Weeks
Lung
Alveolar/bronchiolar Adenoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Alveolar/bronchiolar Carcinoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Alveolar/bronchiolar Adenoma or Carcinoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Histiocytic Sarcoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Malignant Lymphoma | 0/15 (0%) | 1/15 (7%) | 1/30 (3%)
| Aspartame | Glycidol | Total
40 Weeks
Lung
Alveolar/bronchiolar Adenoma | 0/15 (0%) | 1/15 (7%) | 1/30 (3%)
Alveolar/bronchiolar Carcinoma | 0/15 (0%) | 2/15 (13%) | 2/30 (7%)
Alveolar/bronchiolar Adenoma or Carcinoma | 0/15 (0%) | 3/15 (20%) | 3/30 (10%)
Histiocytic Sarcoma | 2/15 (13%) | 2/15 (13%) | 4/30 (13%)
Malignant Lymphoma | 0/15 (0%) | 2/15 (13%) | 2/30 (7%)

a Data as of July 6, 2006

TABLE F2 Historical Incidences of Nonneoplastic Lesions in Control Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice^a^

| Benzene | Phenolphthalein | Total
27 Weeks
Kidney
Casts Protein | 1/15 (7%) | 0/14 (0%) | 1/29 (3%)
Nephropathy | 1/15 (7%) | 6/14 (43%) | 7/29 (24%)
Liver
Inflammation, Chronic | 3/15 (20%) | 11/15 (73%) | 14/30 (47%)
Spleen
Hematopoietic Cell Proliferation | 0/15 (0%) | 2/14 (14%) | 2/29 (7%)
Adrenal Cortex
Subcapsular Hyperplasia | 0/15 (0%) | 0/14 (0%) | 0/29 (0%)
Lung
Inflammation | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Inflammation, Chronic | 2/15 (13%) | 0/15 (0%) | 2/30 (7%)
Stomach, Glandular
Mineralization | 0/15 (0%) | 0/14 (0%) | 0/29 (0%)
Muscularis Mineralization | 0/15 (0%) | 0/14 (0%) | 0/29 (0%)
Heart
Myocardium Degeneration | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Myocardium Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Myocardium Necrosis | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
| Aspartame | Glycidol | Total
40 Weeks
Kidney
Casts Protein | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Nephropathy | 2/15 (13%) | 4/15 (27%) | 6/30 (20%)
Liver
Inflammation, Chronic | 0/15 (0%) | 6/15 (40%) | 6/30 (20%)
Spleen
Hematopoietic Cell Proliferation | 0/15 (0%) | 4/15 (27%) | 4/30 (13%)
Adrenal Cortex
Subcapsular Hyperplasia | 2/15 (13%) | 1/15 (7%) | 3/30 (10%)
Lung
Inflammation | 0/15 (0%) | 3/15 (20%) | 3/30 (10%)
Inflammation, Chronic | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Stomach, Glandular
Mineralization | 0/15 (0%) | 10/15 (67%) | 10/30 (33%)
Muscularis Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Heart
Myocardium Degeneration | 0/15 (0%) | 2/15 (13%) | 2/30 (7%)
Myocardium Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Myocardium Necrosis | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)

a Data as of July 6, 2006

TABLE F3 Historical Incidences of Neoplasms in Control Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice^a^

| Benzene | Phenolphthalein | Total
27 Weeks
Lung
Alveolar/bronchiolar Adenoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Alveolar/bronchiolar Carcinoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Alveolar/bronchiolar Adenoma or Carcinoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Histiocytic Sarcoma | 3/15 (20%) | 0/15 (0%) | 3/30 (10%)
Malignant Lymphoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
| Aspartame | Glycidol | Total
40 Weeks
Lung
Alveolar/bronchiolar Adenoma | 1/15 (7%) | 0/15 (0%) | 1/30 (3%)
Alveolar/bronchiolar Carcinoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Alveolar/bronchiolar Adenoma or Carcinoma | 1/15 (7%) | 0/15 (0%) | 1/30 (3%)
Histiocytic Sarcoma | 5/15 (33%) | 9/15 (60%) | 14/30 (47%)
Malignant Lymphoma | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)

a Data as of July 6, 2006

TABLE F4 Historical Incidences of Nonneoplastic Lesions in Control Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice^a^

| Benzene | Phenolphthalein | Total
27 Weeks
Kidney
Casts Protein | 5/15 (33%) | 0/15 (0%) | 5/30 (17%)
Nephropathy | 3/15 (20%) | 10/15 (67%) | 13/30 (43%)
Liver
Inflammation, Chronic | 10/15 (67%) | 10/15 (67%) | 20/30 (67%)
Spleen
Hematopoietic Cell Proliferation | 5/15 (33%) | 2/15 (13%) | 7/30 (23%)
Uterus
Endometrium Hyperplasia Cystic | 12/15 (80%) | 15/15 (100%) | 27/30 (90%)
Ovary
Cyst | 1/14 (7%) | 1/15 (7%) | 2/29 (7%)
Lung
Inflammation | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Inflammation, Chronic | 2/15 (13%) | 2/15 (13%) | 4/30 (13%)
Stomach, Glandular
Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Muscularis Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Heart
Myocardium Degeneration | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Myocardium Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Myocardium Necrosis | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
| Aspartame | Glycidol | Total
40 Weeks
Kidney
Casts Protein | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Nephropathy | 1/15 (7%) | 12/15 (80%) | 13/30 (43%)
Liver
Inflammation, Chronic | 1/15 (7%) | 11/15 (73%) | 12/30 (40%)
Spleen
Hematopoietic Cell Proliferation | 5/15 (33%) | 9/15 (60%) | 14/30 (47%)
Uterus
Endometrium Hyperplasia Cystic | 14/15 (93%) | 13/15 (87%) | 27/30 (90%)
Adrenal Cortex
Subcapsular Hyperplasia | 14/15 (93%) | 15/15 (100%) | 29/30 (97%)
Ovary
Cyst | 0/15 (0%) | 4/15 (27%) | 4/30 (13%)
Lung
Inflammation | 0/15 (0%) | 8/15 (53%) | 8/30 (27%)
Inflammation, Chronic | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Stomach, Glandular
Mineralization | 0/15 (0%) | 4/15 (27%) | 4/30 (13%)
Muscularis Mineralization | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Heart
Myocardium Degeneration | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)
Myocardium Mineralization | 0/15 (0%) | 1/15 (7%) | 1/30 (3%)
Myocardium Necrosis | 0/15 (0%) | 0/15 (0%) | 0/30 (0%)

a Data as of July 6, 2006