# APPENDIX E CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization of Glycidol

Glycidol was obtained from Aldrich Chemical Co. (Milwaukee, WI) in one lot (01616 BS) and was used in the 40-week study. Identity and purity analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC), and the study laboratory, Battelle Columbus Operations (Columbus, OH); stability analyses were also conducted by the analytical chemistry laboratory. Reports on analyses performed in support of the glycidol studies are on file at the National Institute of Environmental Health Sciences.

Lot 01616 BS of the chemical, a viscous, colorless, combustible liquid (NTP, 2004), was identified as glycidol using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy by the analytical chemistry laboratory and IR spectroscopy by the study laboratory. Spectra were consistent with the structure of glycidol, matched reference spectra (Aldrich, 1981, 1983, 1985), and matched the spectrum of a reference standard from the same lot. Representative IR and NMR spectra are presented in Figures E1 and E2, respectively.

The purity of lot 01616 BS was determined by the analytical chemistry and study laboratories using gas chromatography (GC). The analytical chemistry laboratory GC system included flame ionization detection (FID; Hewlett-Packard, Palo Alto, CA), a Supelco Nukol column (30 m × 0.25 mm, 0.25-µm film thickness; Supelco, Bellefonte, PA), an oven temperature program of 60° C to 200° C at 10° C/minute, held 26 minutes, and helium as the carrier gas at a flow rate of 1.0 mL/minute. For the impurity identification, the analytical laboratory used an Agilent 6890 GC with a 5973 mass spectrometry detector (Palo Alto, CA) and a Supelco (Bellefonte, PA) Nukol column (30 m × 0.32 mm ID, 0.25-µm film thickness). The oven program was 60° C for 5 minutes, 60° C to 200° C at 10° C/minute, then 200° C for 26 minutes. Helium was the carrier gas at 1.6 mL/minute and electron impact ionization. Quantitation of the impurity peaks was performed with a GC/FID system similar to the system described above. The study laboratory system included a GC/FID (Hewlett-Packard, Palo Alto, CA); a Stabilwax DA column (30 m × 0.25 mm, 0.25-µm film thickness; Restek, Bellefonte, PA); an oven temperature program of 60° C to 200° C at 15° C/minute, held 5 minutes, and helium as the carrier gas at a flow rate of 1 mL/minute.

GC by the analytical chemistry laboratory indicated one major peak, six impurities with peak areas greater than 0.1% of the total peak area, ranging from 0.12% to 1.18%, and seven impurities with peak areas less than 0.1% of the total peak area; the purity of lot 01616 BS was determined to be greater than 96%. Impurities with peak areas exceeding 0.1% were 1-hydroxy-2-propanone (0.6%), diglycidyl ether (0.3%), 3-methoxy-1,2-propanediol (0.5%), 2,5-dimethanol-p-dioxane (0.1%), 2,6-dimethanol-p-dioxane (2.2%), and glycidol-dimethyl ether (0.2%). GC by the study laboratory indicated one major peak and several minor impurities; the purity was determined to be 95.9% by comparison to a reference standard from the same lot. The overall purity of lot 01616 BS was determined to be greater than 95%.

Analyses of the bulk chemical were performed by the study laboratory at approximately 2 and 8 months after the study began and at the end of the study using GC by the system previously described. To ensure stability, the bulk chemical was protected from light in amber glass bottles capped with Teflon^®^-lined lids and stored at approximately 5° C. No degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared at least every month. The dose formulations were prepared by mixing the appropriate amount of glycidol with deionized water to give the required concentrations (Table E1). Formulations were protected from light in amber glass bottles capped with Teflon^®^-lined lids and stored at approximately 5° C for up to 35 days.

The study laboratory conducted periodic analyses of preadministration dose formulations five times during the study using GC by the system previously described with variations in the oven temperature program (60° C for 1.5 minutes, then 200° C at 20° C/minute, held 7 minutes); postadministration formulations were also analyzed. Of the preadministration dose formulations analyzed, all were within 10% of the target concentrations; of the postadministration formulations analyzed, all 16 were more than 10% less than the target concentrations, ranging from −11% to −17%, probably due to the evaporation of glycidol during administration (Table E2).

FIGURE E1 Infrared Absorption Spectrum of Glycidol

FIGURE E2 Proton Nuclear Magnetic Resonance Spectrum of Glycidol

TABLE E1 Preparation and Storage of Dose Formulations in the 40-Week Gavage Study of Glycidol

Preparation
Dose formulations were prepared at least every 3 months. For each formulation, the appropriate amount of the chemical was pipetted into a calibrated mixing bottle containing deionized water, diluted to volume, and thoroughly mixed.
Chemical Lot Number
01616 BS
Maximum Storage Time
35 days
Storage Conditions
Protected from light in amber glass bottles capped with Teflon^®^-lined lids and stored at approximately 5° C
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

TABLE E2 Results of Analyses of Dose Formulations Administered to Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
January 26, 2000 | January 27, 2000 | 2.5 | 2.409 | −4
January 26, 2000 | January 27, 2000 | 5 | 4.864 | −3
January 26, 2000 | January 27, 2000 | 10 | 9.749 | −3
January 26, 2000 | January 27, 2000 | 20 | 19.79 | −1
January 26, 2000 | March 2-3, 2000^b^ | 2.5 | 2.164 | −13
January 26, 2000 | March 2-3, 2000^b^ | 5 | 4.280 | −14
January 26, 2000 | March 2-3, 2000^b^ | 10 | 8.619 | −14
January 26, 2000 | March 2-3, 2000^b^ | 20 | 17.78 | −11
April 21, 2000 | April 25-26, 2000 | 2.5 | 2.374 | −5
April 21, 2000 | April 25-26, 2000 | 5 | 4.831 | −3
April 21, 2000 | April 25-26, 2000 | 10 | 10.12 | +1
April 21, 2000 | April 25-26, 2000 | 20 | 20.09 | 0
April 21, 2000 | May 30-31, 2000^b^ | 2.5 | 2.066 | −17
April 21, 2000 | May 30-31, 2000^b^ | 5 | 4.128 | −17
April 21, 2000 | May 30-31, 2000^b^ | 10 | 8.583 | −14
April 21, 2000 | May 30-31, 2000^b^ | 20 | 17.42 | −13
July 13, 2000 | July 14-15, 2000 | 2.5 | 2.296 | −8
July 13, 2000 | July 14-15, 2000 | 5 | 4.649 | −7
July 13, 2000 | July 14-15, 2000 | 10 | 9.368 | −6
July 13, 2000 | July 14-15, 2000 | 20 | 19.55 | −2
July 13, 2000 | August 22, 2000^b^ | 2.5 | 2.197 | −12
July 13, 2000 | August 22, 2000^b^ | 5 | 4.321 | −14
July 13, 2000 | August 22, 2000^b^ | 10 | 8.276 | −17
July 13, 2000 | August 22, 2000^b^ | 20 | 16.62 | −17
October 5, 2000 | October 11, 2000 | 2.5 | 2.392 | −4
October 5, 2000 | October 11, 2000 | 5 | 4.770 | −5
October 5, 2000 | October 11, 2000 | 10 | 9.318 | −7
October 5, 2000 | October 11, 2000 | 20 | 18.82 | −6
October 5, 2000 | November 14-15, 2000^b^ | 2.5 | 2.217 | −11
October 5, 2000 | November 14-15, 2000^b^ | 5 | 4.252 | −15
October 5, 2000 | November 14-15, 2000^b^ | 10 | 8.502 | −15
October 5, 2000 | November 14-15, 2000^b^ | 20 | 17.24 | −14

a Results of duplicate analysis

b Animal room samples