# APPENDIX D REPRODUCTIVE TISSUE EVALUATIONS

TABLE D1 Summary of Reproductive Tissue Evaluations in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
n | 13 | 14 | 13 | 14 | 7
Weights (g)
Necropsy body weight | 48.9 ± 0.9 | 47.5 ± 1.1 | 48.7 ± 0.5 | 47.4 ± 1.2 | 40.8 ± 2.4^**^
L. Cauda epididymis | 0.0162 ± 0.0005 | 0.0154 ± 0.0004 | 0.0152 ± 0.0004 | 0.0150 ± 0.0004 | 0.0131 ± 0.0005^**^
L. Epididymis | 0.0506 ± 0.0008 | 0.0499 ± 0.0009 | 0.0488 ± 0.0012 | 0.0490 ± 0.0010 | 0.0432 ± 0.0023^**^
L. Testis | 0.1250 ± 0.0022 | 0.1237 ± 0.0025 | 0.1243 ± 0.0024 | 0.1250 ± 0.0027 | 0.1118 ± 0.0045^*^
Spermatid measurements
Spermatid heads (10^6^/g testis) | 170.6 ± 9.8^b^ | 185.7 ± 6.5^c^ | 181.9 ± 8.4 | 185.1 ± 5.8^c^ | 169.3 ± 6.3
Spermatid heads (10^6^/testis) | 18.89 ± 0.79^b^ | 20.27 ± 0.72 | 20.54 ± 0.88 | 20.70 ± 0.61 | 17.29 ± 0.92
Epididymal spermatozoal measurements
Sperm motility (%) | 90.99 ± 0.90 | 90.18 ± 1.36 | 91.29 ± 0.68 | 90.17 ± 0.86 | 91.27 ± 0.60
Sperm heads (10^6^/g cauda epididymis) | 838 ± 34 | 799 ± 35 | 797 ± 44 | 840 ± 23 | 599 ± 105
Sperm heads (10^6^/cauda) | 13.52 ± 0.59 | 12.29 ± 0.62 | 11.97 ± 0.35 | 12.59 ± 0.40 | 8.07 ± 1.56^**^

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test

** Significantly different (P≤0.01) from the vehicle control group by Dunnett’s (body weights), Williams’ (left cauda epididymis and epididymis weights), or Dunn’s (sperm heads per cauda) test

a Data are presented as mean ± standard error. Differences from the vehicle control group for spermatid, epididymal sperm heads per gram cauda, and epididymal sperm motility measurements are not significant by Dunn’s test.

b n=12

c n=13