# APPENDIX C ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE C1 Organ Weights and Organ-Weight-to-Body-Weight Ratios in Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
n | 13 | 14 | 13 | 14 | 7
Necropsy body wt | 48.9 ± 0.9 | 47.5 ± 1.1 | 48.7 ± 0.5 | 47.4 ± 1.2 | 40.8 ± 2.4^**^
Heart
Absolute | 0.237 ± 0.005 | 0.237 ± 0.007 | 0.226 ± 0.006 | 0.227 ± 0.006 | 0.190 ± 0.007^**^
Relative | 4.841 ± 0.076 | 5.000 ± 0.132 | 4.643 ± 0.118 | 4.788 ± 0.107 | 4.695 ± 0.172
R. Kidney
Absolute | 0.394 ± 0.016 | 0.403 ± 0.017 | 0.381 ± 0.009 | 0.392 ± 0.010 | 0.356 ± 0.010
Relative | 8.035 ± 0.264 | 8.468 ± 0.260 | 7.824 ± 0.173 | 8.286 ± 0.185 | 8.852 ± 0.373
Liver
Absolute | 2.672 ± 0.144 | 2.709 ± 0.163 | 2.936 ± 0.140 | 2.495 ± 0.134 | 2.109 ± 0.115
Relative | 54.317 ± 2.279 | 56.573 ± 2.322 | 60.284 ± 2.831 | 52.254 ± 1.862 | 52.939 ± 5.006
Lung
Absolute | 0.355 ± 0.020 | 0.336 ± 0.013 | 0.321 ± 0.007 | 0.375 ± 0.020 | 0.325 ± 0.021
Relative | 7.291 ± 0.445 | 7.127 ± 0.328 | 6.597 ± 0.140 | 8.086 ± 0.693 | 8.157 ± 0.753
R. Testis
Absolute | 0.128 ± 0.003 | 0.125 ± 0.003 | 0.127 ± 0.003 | 0.128 ± 0.003 | 0.112 ± 0.002^**^
Relative | 2.626 ± 0.065 | 2.654 ± 0.067 | 2.609 ± 0.055 | 2.715 ± 0.048 | 2.793 ± 0.134
Thymus
Absolute | 0.051 ± 0.004 | 0.049 ± 0.003 | 0.054 ± 0.005 | 0.049 ± 0.004 | 0.038 ± 0.003
Relative | 1.043 ± 0.084 | 1.038 ± 0.049 | 1.117 ± 0.091 | 1.025 ± 0.089 | 0.922 ± 0.058
Female
n | 13 | 14 | 12 | 14 | 9
Necropsy body wt | 42.4 ± 2.0 | 39.8 ± 1.3 | 36.6 ± 1.6^**^ | 35.1 ± 1.2^**^ | 31.4 ± 0.9^**^
Heart
Absolute | 0.184 ± 0.004 | 0.185 ± 0.007 | 0.183 ± 0.008 | 0.169 ± 0.004 | 0.165 ± 0.009
Relative | 4.424 ± 0.150 | 4.673 ± 0.144 | 5.047 ± 0.242 | 4.855 ± 0.148 | 5.298 ± 0.352^**^
R. Kidney
Absolute | 0.254 ± 0.007 | 0.252 ± 0.005 | 0.261 ± 0.006 | 0.266 ± 0.007 | 0.262 ± 0.006
Relative | 6.092 ± 0.196 | 6.413 ± 0.246 | 7.262 ± 0.293^**^ | 7.666 ± 0.297^**^ | 8.365 ± 0.175^**^
Liver
Absolute | 2.051 ± 0.093 | 1.892 ± 0.068 | 2.133 ± 0.204 | 2.201 ± 0.295 | 1.904 ± 0.295
Relative | 48.670 ± 1.112 | 48.056 ± 2.088 | 60.141 ± 7.744 | 64.043 ± 9.728 | 60.539 ± 8.937
Lung
Absolute | 0.334 ± 0.019 | 0.378 ± 0.010^b^ | 0.370 ± 0.019 | 0.345 ± 0.019 | 0.340 ± 0.021
Relative | 8.363 ± 0.920 | 9.361 ± 0.277^b^ | 10.242 ± 0.575 | 9.986 ± 0.730 | 10.901 ± 0.748^*^
Thymus
Absolute | 0.052 ± 0.004 | 0.049 ± 0.004 | 0.042 ± 0.005 | 0.047 ± 0.003 | 0.035 ± 0.002^*^
Relative | 1.216 ± 0.061 | 1.211 ± 0.068 | 1.134 ± 0.108 | 1.355 ± 0.075 | 1.108 ± 0.067

* Significantly different (P≤0.05) from the vehicle control group by William’s or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as _b_ mg organ weight/g body weight (mean ± standard error).

b n=13