# APPENDIX B GENETIC TOXICOLOGY

TABLE B1 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent of Polychromatic Erythrocytes in Peripheral Blood of Haploinsufficient p16^Ink4a^/p19^Arf^ Mice Administered Glycidol by Gavage^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)
6.5 Weeks
Male
Water^d^ | | 15 | 2.13 ± 0.19 | | 2.4
Glycidol | 25 | 15 | 1.87 ± 0.24 | 0.7676 | 1.9
Glycidol | 50 | 15 | 2.13 ± 0.24 | 0.5000 | 2.1
Glycidol | 100 | 15 | 2.27 ± 0.28 | 0.3637 | 1.8
Glycidol | 200 | 15 | 2.77 ± 0.27 | 0.0583 | 2.4
Glycidol | | | P=0.013^e^
Female
Water | | 15 | 1.13 ± 0.17 | | 2.0
Glycidol | 25 | 15 | 1.30 ± 0.22 | 0.2791 | 2.3
Glycidol | 50 | 15 | 2.10 ± 0.22 | 0.0016 | 2.1
Glycidol | 100 | 15 | 2.03 ± 0.26 | 0.0028 | 2.1
Glycidol | 200 | 15 | 1.77 ± 0.24 | 0.0208 | 2.6
Glycidol | | | P=0.032
13 Weeks
Male
Water | | 15 | 1.60 ± 0.21 | | 1.9
Glycidol | 25 | 15 | 1.50 ± 0.20 | 0.6222 | 1.8
Glycidol | 50 | 15 | 1.37 ± 0.20 | 0.7711 | 2.0
Glycidol | 100 | 15 | 1.83 ± 0.18 | 0.2450 | 2.0
Glycidol | 200 | 15 | 2.00 ± 0.24 | 0.1239 | 2.2
Glycidol | | | P=0.036
Female
Water | | 14 | 1.43 ± 0.23 | | 2.1
Glycidol | 25 | 15 | 0.87 ± 0.17 | 0.9776 | 2.0
Glycidol | 50 | 15 | 1.23 ± 0.21 | 0.7406 | 2.4
Glycidol | 100 | 15 | 1.23 ± 0.25 | 0.7406 | 2.0
Glycidol | 200 | 15 | 1.63 ± 0.22 | 0.2645 | 2.5
Glycidol | | | P=0.046
19.5 Weeks
Male
Water | | 15 | 1.33 ± 0.24 | | 2.8
Glycidol | 25 | 15 | 1.27 ± 0.34 | 0.5672 | 2.5
Glycidol | 50 | 15 | 1.87 ± 0.35 | 0.1111 | 2.4
Glycidol | 100 | 15 | 1.57 ± 0.28 | 0.2874 | 2.4
Glycidol | 200 | 15 | 2.50 ± 0.34 | 0.0073 | 2.5
Glycidol | | | P=0.002
Female
Water | | 14 | 0.64 ± 0.13 | | 2.7
Glycidol | 25 | 15 | 1.27 ± 0.32 | 0.0372 | 2.4
Glycidol | 50 | 15 | 1.13 ± 0.34 | 0.0727 | 2.3
Glycidol | 100 | 15 | 1.37 ± 0.22 | 0.0218 | 2.6
Glycidol | 200 | 14 | 1.46 ± 0.30 | 0.0135 | 2.9
Glycidol | | | P=0.040
26 Weeks
Male
Water | | 15 | 1.93 ± 0.27 | | 2.9
Glycidol | 25 | 15 | 1.80 ± 0.21 | 0.6474 | 2.9
Glycidol | 50 | 14 | 2.54 ± 0.23 | 0.0619 | 3.0
Glycidol | 100 | 15 | 2.90 ± 0.35 | 0.0079 | 2.5
Glycidol | 200 | 14 | 3.82 ± 0.35 | 0.0000 | 2.3
Glycidol | | | P=0.000
Female
Water | | 14 | 1.07 ± 0.21 | | 2.7
Glycidol | 25 | 15 | 1.20 ± 0.19 | 0.3231 | 2.7
Glycidol | 50 | 15 | 1.17 ± 0.17 | 0.3660 | 3.1
Glycidol | 100 | 15 | 1.37 ± 0.17 | 0.1548 | 2.3
Glycidol | 200 | 14 | 2.07 ± 0.27 | 0.0014 | 3.1
Glycidol | | | P=0.000
40 Weeks
Male
Water | | 13 | 1.81 ± 0.41 | | 3.1
Glycidol | 25 | 14 | 1.71 ± 0.21 | 0.6021 | 3.1
Glycidol | 50 | 13 | 2.31 ± 0.30 | 0.1042 | 4.4
Glycidol | 100 | 14 | 2.61 ± 0.24 | 0.0243 | 4.6
Glycidol | 200 | 7 | 3.64 ± 0.61 | 0.0002 | 3.9
Glycidol | | | P=0.000
Female
Water | | 13 | 1.31 ± 0.14 | | 4.4
Glycidol | 25 | 14 | 1.89 ± 0.24 | 0.0451 | 4.7
Glycidol | 50 | 12 | 1.88 ± 0.39 | 0.0553 | 7.0
Glycidol | 100 | 14 | 2.32 ± 0.26 | 0.0030 | 7.2
Glycidol | 200 | 9 | 2.83 ± 0.40 | 0.0002 | 4.5
Glycidol | | | P=0.000

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte, NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.006 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)