# APPENDIX A SUMMARY OF LESIONS IN HAPLOINSUFFICIENT p16^Ink4a^/p19^Arf^ MICE IN THE GAVAGE STUDY OF GLYCIDOL

TABLE A1 Summary of the Incidence of Neoplasms in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Early deaths
Accidental death | | | | | 1
Moribund | | | 1 | | 4
Natural deaths | 2 | 1 | 1 | 1 | 3
Survivors
Terminal sacrifice | 13 | 14 | 13 | 14 | 7
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine large, rectum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 1 (7%) | | 1 (7%)
Intestine large, cecum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 1 (7%)
Intestine small, duodenum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 1 (7%) | | 2 (13%)
Intestine small, jejunum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 2 (13%) | 1 (7%)
Intestine small, ileum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | | 1 (7%)
Liver | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 2 (13%) | 2 (13%) | 4 (27%) | 2 (13%) | 10 (67%)
Pancreas | | | | | (1)
Histiocytic sarcoma | | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma, multiple | | | | | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | | | 5 (33%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (14) | (15)
Histiocytic sarcoma | | | | 1 (7%) | 1 (7%)
Pituitary gland | (15) | (15) | (14) | (15) | (15)
Histiocytic sarcoma | | | | | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | 2 (13%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 2 (13%) | 5 (33%) | 6 (40%) | 4 (27%) | 8 (53%)
Lymph node | (14) | (14) | (15) | (13) | (13)
Mediastinal, histiocytic sarcoma | | 1 (7%) | 3 (20%) | | 7 (54%)
Mediastinal, osteosarcoma, metastatic, skin | 1 (7%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%) | 1 (7%) | 2 (13%) | | 3 (20%)
Lymph node, mesenteric | (15) | (15) | (15) | (14) | (15)
Histiocytic sarcoma | | 1 (7%) | 2 (13%) | 1 (7%) | 5 (33%)
Spleen | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%) | 1 (7%) | 3 (20%) | 1 (7%) | 7 (47%)
Thymus | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 2 (13%) | 2 (13%) | 4 (27%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15)
Osteosarcoma | 1 (7%)
Squamous cell papilloma | | 1 (7%)
Musculoskeletal System
Skeletal muscle | | | | (1)
Hemangiosarcoma | | | | 1 (100%)
Nervous System
Brain | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 1 (7%) | 1 (7%) | 4 (27%)
Spinal cord | | | | (1)
Histiocytic sarcoma | | | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 1 (7%) | | 2 (13%) | 5 (33%) | 2 (13%)
Alveolar/bronchiolar adenoma, multiple | | | | 2 (13%) | 1 (7%)
Alveolar/bronchiolar carcinoma | 2 (13%) | | 1 (7%) | 3 (20%)
Alveolar/bronchiolar carcinoma, multiple | | 1 (7%)
Histiocytic sarcoma | 1 (7%) | 1 (7%) | 2 (13%) | 2 (13%) | 6 (40%)
Osteosarcoma, metastatic, skin | 1 (7%)
Special Senses System
Harderian gland | | (1)
Adenoma | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 2 (13%) | 2 (13%) | 5 (33%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 2 (13%) | 6 (40%) | 9 (60%) | 5 (33%) | 11 (73%)
Lymphoma malignant | 2 (13%) | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 8 | 12 | 12 | 12
Total primary neoplasms | 8 | 9 | 12 | 17 | 15
Total animals with benign neoplasms | 1 | 2 | 2 | 7 | 4
Total benign neoplasms | 1 | 2 | 2 | 7 | 4
Total animals with malignant neoplasms | 6 | 7 | 10 | 9 | 11
Total malignant neoplasms | 7 | 7 | 10 | 10 | 11
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Early deaths
Accidental death | | | | | 1
Moribund | | | 1 | | 4
Natural deaths | 2 | 1 | 1 | 1 | 3
Survivors
Terminal sacrifice | 13 | 14 | 13 | 14 | 7
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Esophagus | | | (1)
Inflammation, acute | | | 1 (100%)
Intestine small, jejunum | (15) | (15) | (15) | (15) | (15)
Peyer’s patch, hyperplasia, atypical | | 1 (7%)
Peyer’s patch, hyperplasia, lymphoid | | 1 (7%)
Liver | (15) | (15) | (15) | (15) | (15)
Angiectasis, focal | | | | | 1 (7%)
Basophilic focus | | 1 (7%)
Degeneration, cystic | 1 (7%)
Eosinophilic focus | | | | | 1 (7%)
Fatty change, focal | | | | 1 (7%)
Hematopoietic cell proliferation | | 1 (7%) | | 2 (13%) | 1 (7%)
Hemorrhage | | | 1 (7%)
Infiltration cellular, lymphoid | 1 (7%) | 2 (13%) | | 2 (13%) | 1 (7%)
Inflammation, chronic | 6 (40%) | 9 (60%) | 8 (53%) | 9 (60%) | 2 (13%)
Mixed cell focus | | | | 1 (7%)
Necrosis, focal | 1 (7%) | 2 (13%) | 2 (13%) | | 5 (33%)
Mesentery | | (1)
Fat, necrosis | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | | | | | 1 (7%)
Ulcer | | 1 (7%) | | | 3 (20%)
Epithelium, hyperplasia | | 1 (7%) | 1 (7%) | | 6 (40%)
Stomach, glandular | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | | | 1 (7%)
Mineralization | 10 (67%) | | | 5 (33%) | 1 (7%)
Ulcer | | | | | 1 (7%)
Epithelium, hyperplasia | | 1 (7%)
Glands, ectasia | | | 1 (7%)
Muscularis, mineralization | | | | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, mast cell | | | | | 1 (7%)
Epicardium, inflammation, chronic | 1 (7%)
Myocardium, degeneration | 2 (13%) | | | 2 (13%)
Myocardium, mineralization | | | 2 (13%) | 1 (7%) | 5 (33%)
Myocardium, necrosis | | | | | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (14) | (15)
Hyperplasia, focal | 1 (7%) | | | 1 (7%)
Subcapsular, hyperplasia | 1 (7%) | 2 (13%) | 2 (13%) | 3 (21%) | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (15)
Fibrosis | | 1 (7%)
Preputial gland | | | (1)
Inflammation, suppurative | | | 1 (100%)
Testes | (15) | (15) | (15) | (15) | (15)
Germinal epithelium, degeneration | | 1 (7%) | | | 1 (7%)
Germinal epithelium, mineralization | | 1 (7%)
Germinal epithelium, necrosis | 1 (7%)
Hematopoietic System
Lymph node | (14) | (14) | (15) | (13) | (13)
Mediastinal, hyperplasia, lymphoid | | 1 (7%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | | 2 (13%) | | 1 (7%)
Inflammation, suppurative | | | 1 (7%)
Necrosis | | | | | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (14) | (15)
Hematopoietic cell proliferation | | 1 (7%)
Hyperplasia, lymphoid | | 2 (13%) | | 1 (7%) | 1 (7%)
Inflammation, suppurative | | 1 (7%) | | | 1 (7%)
Necrosis | | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (15)
Angiectasis | | | | | 1 (7%)
Atrophy | | | | 1 (7%) | 2 (13%)
Hematopoietic cell proliferation | 4 (27%) | 7 (47%) | 7 (47%) | 5 (33%) | 5 (33%)
Thymus | (15) | (15) | (15) | (15) | (15)
Atrophy | 2 (13%) | | 1 (7%) | | 4 (27%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15)
Ulcer | | | | | 1 (7%)
Musculoskeletal System
Bone | (15) | (15) | (15) | (15) | (15)
Hyperostosis | 1 (7%)
Nervous System
Brain | (15) | (15) | (15) | (15) | (15)
Mineralization | 1 (7%)
Cerebellum, gliosis | | | | | 2 (13%)
Cerebellum, hemorrhage, focal | | | | | 1 (7%)
Cerebellum, neuronopathy | | | | | 3 (20%)
Cerebrum, hemorrhage | | | | | 1 (7%)
Cerebrum, necrosis, focal | | | | | 2 (13%)
Hippocampus, hemorrhage | | | | | 1 (7%)
Hippocampus, necrosis | | | 1 (7%) | | 1 (7%)
Medulla, gliosis | | | | | 2 (13%)
Medulla, neuronopathy | | | | | 3 (20%)
Thalamus, gliosis | | | | | 2 (13%)
Thalamus, neuronopathy | | | | | 5 (33%)
Spinal cord | | | | (1)
Axon, degeneration | | | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Hemorrhage | | | | | 1 (7%)
Inflammation | 3 (20%) | 7 (47%) | 5 (33%) | 4 (27%) | 2 (13%)
Inflammation, granulomatous | | | 1 (7%)
Alveolar epithelium, hyperplasia, focal | | 2 (13%) | | 2 (13%) | 2 (13%)
Bronchiole, hyperplasia | | | 1 (7%)
Vein, thrombosis | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Hydronephrosis | | | | | 1 (7%)
Infarct | | | | | 1 (7%)
Nephropathy | 4 (27%) | 5 (33%) | 5 (33%) | 4 (27%) | 4 (27%)
Renal tubule, accumulation, hyaline droplet | | | 1 (7%) | | 1 (7%)
Urinary bladder | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | | | | | 1 (7%)
Transitional epithelium, hyperplasia | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1 | 2 | 1 | 4
Natural deaths | | | 1 | | 2
Survivors
Terminal sacrifice | 13 | 14 | 12 | 14 | 9
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine large, colon | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | 1 (7%)
Intestine large, rectum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | | 1 (7%)
Intestine small, duodenum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 4 (27%) | 1 (7%) | 1 (7%)
Intestine small, jejunum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 3 (20%) | 3 (20%) | 1 (7%)
Intestine small, ileum | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 2 (13%) | 2 (13%) | 1 (7%) | 1 (7%)
Liver | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 5 (33%) | 1 (7%) | 8 (53%) | 5 (33%) | 8 (53%)
Osteosarcoma, metastatic, uncertain primary site | | 1 (7%)
Mesentery | | | (2)
Histiocytic sarcoma | | | 2 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | | 1 (7%)
Squamous cell papilloma | | | | 1 (7%) | 3 (20%)
Stomach, glandular | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 1 (7%) | 2 (13%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 2 (13%) | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 3 (20%) | | 7 (47%) | 2 (13%) | 1 (7%)
Adrenal medulla | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%)
Pituitary gland | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%) | | 2 (13%) | 1 (7%) | 1 (7%)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 8 (53%) | 5 (33%) | 8 (53%) | 6 (40%) | 5 (33%)
Osteosarcoma, metastatic, uncertain primary site | | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (15)
Hemangiosarcoma, metastatic, spleen | | | 1 (7%)
Histiocytic sarcoma | | | 4 (27%) | 4 (27%) | 5 (33%)
Sarcoma stromal | | | | | 1 (7%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15)
Hemangiosarcoma | | | | 1 (7%)
Histiocytic sarcoma | 9 (60%) | 8 (53%) | 11 (73%) | 8 (53%) | 8 (53%)
Lymph node | (13) | (15) | (15) | (13) | (14)
Lumbar, histiocytic sarcoma | | 2 (13%) | 1 (7%) | | 2 (14%)
Mediastinal, histiocytic sarcoma | 1 (8%) | 1 (7%) | 6 (40%) | 3 (23%) | 3 (21%)
Pancreatic, histiocytic sarcoma | | | 1 (7%)
Renal, histiocytic sarcoma | | 2 (13%) | | | 1 (7%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%) | 1 (7%) | 6 (40%) | 2 (13%) | 3 (20%)
Lymph node, mesenteric | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 3 (20%) | 3 (20%) | 5 (33%) | 3 (20%) | 5 (33%)
Spleen | (15) | (15) | (15) | (15) | (15)
Hemangiosarcoma | | | 1 (7%)
Histiocytic sarcoma | 2 (13%) | 2 (13%) | 7 (47%) | 3 (20%) | 2 (13%)
Thymus | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%) | 1 (7%) | 6 (40%) | 2 (13%) | 2 (13%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15)
Subcutaneous tissue, hemangiosarcoma | 1 (7%)
Subcutaneous tissue, histiocytic sarcoma | | | 2 (13%) | | 1 (7%)
Musculoskeletal System
Skeletal muscle | | | | | (2)
Histiocytic sarcoma | | | | | 2 (100%)
Nervous System
Brain | (15) | (15) | (15) | (15) | (15)
Choristoma | | | | | 1 (7%)
Histiocytic sarcoma | 1 (7%) | | 4 (27%) | 4 (27%) | 2 (13%)
Spinal cord | | | | | (1)
Histiocytic sarcoma | | | | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | | 1 (7%) | | 1 (7%) | 4 (27%)
Alveolar/bronchiolar carcinoma | | | | 1 (7%)
Histiocytic sarcoma | 2 (13%) | | 6 (40%) | 3 (20%) | 6 (40%)
Osteosarcoma, metastatic, uncertain primary site | | 1 (7%)
Special Senses System
Zymbal’s gland | | | | (1) | (1)
Squamous cell carcinoma | | | | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%) | | 4 (27%) | 2 (13%) | 3 (20%)
Urinary bladder | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 2 (13%) | 2 (13%) | 2 (13%)
Systemic Lesions
Multiple organsy^b^ | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 9 (60%) | 9 (60%) | 12 (80%) | 10 (67%) | 13 (87%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 9 | 12 | 12 | 14
Total primary neoplasms | 10 | 10 | 13 | 14 | 23
Total animals with benign neoplasms | | 1 | | 2 | 7
Total benign neoplasms | | 1 | | 2 | 7
Total animals with malignant neoplasms | 10 | 9 | 12 | 11 | 14
Total malignant neoplasms | 10 | 9 | 13 | 12 | 15
Total animals with metastatic neoplasms | | 1 | 1
Total metastatic neoplasms | | 3 | 1
Total animals with malignant neoplasms
uncertain primary site | | 1
Total animals with uncertain neoplasms-benign or malignant | | | | | 1
Total uncertain neoplasms | | | | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 40-Week Gavage Study of Glycidol^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1 | 2 | 1 | 4
Natural deaths | | | 1 | | 2
Survivors
Terminal sacrifice | 13 | 14 | 12 | 14 | 9
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15)
Angiectasis, focal | | | | 1 (7%) | 2 (13%)
Eosinophilic focus | | | | | 1 (7%)
Hematopoietic cell proliferation | 2 (13%) | 3 (20%) | 1 (7%) | 1 (7%) | 2 (13%)
Infiltration cellular, lymphoid | | 3 (20%) | 1 (7%) | 1 (7%) | 1 (7%)
Inflammation | | 1 (7%)
Inflammation, chronic | 11 (73%) | 10 (67%) | 8 (53%) | 8 (53%) | 7 (47%)
Mixed cell focus | | | 1 (7%) | 1 (7%)
Necrosis, focal | | | 5 (33%) | 2 (13%) | 2 (13%)
Midzonal, fatty change | 1 (7%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Epithelium, hyperplasia | | | | 1 (7%) | 4 (27%)
Stomach, glandular | (15) | (15) | (15) | (15) | (15)
Metaplasia, squamous | | | 1 (7%)
Mineralization | 4 (27%) | | | | 2 (13%)
Epithelium, ectasia | | | 1 (7%)
Muscularis, mineralization | | | | | 2 (13%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | | | | | 1 (7%)
Myocardium, mineralization | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | 1 (7%)
Hyperplasia, focal | | 2 (13%) | | | 1 (7%)
Mineralization | | | | | 1 (7%)
Vacuolization cytoplasmic, focal | 1 (7%)
Subcapsular, hyperplasia | 15 (100%) | 15 (100%) | 10 (67%) | 14 (93%) | 15 (100%)
Pituitary gland | (15) | (15) | (15) | (15) | (15)
Necrosis | | | | | 1 (7%)
Pars distalis, hyperplasia, focal | 1 (7%) | 1 (7%) | 2 (13%) | 1 (7%)
General Body System
None
Genital System
Clitoral gland | | | | | (1)
Pigmentation, melanin | | | | | 1 (100%)
Ovary | (15) | (15) | (15) | (15) | (15)
Cyst | 4 (27%) | | | | 2 (13%)
Uterus | (15) | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 13 (87%) | 14 (93%) | 10 (67%) | 14 (93%) | 9 (60%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15)
Hyperplasia | | | | | 1 (7%)
Lymph node | (13) | (15) | (15) | (13) | (14)
Lumbar, hyperplasia, lymphoid | | 1 (7%)
Mediastinal, hyperplasia, lymphoid | 2 (15%) | 1 (7%)
Pancreatic, hyperplasia, lymphoid | | | | | 1 (7%)
Renal, hyperplasia, lymphoid | | | | | 1 (7%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | 1 (7%) | | | | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | | | | 1 (7%)
Inflammation, suppurative | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 9 (60%) | 5 (33%) | 10 (67%) | 10 (67%) | 10 (67%)
Thymus | (15) | (15) | (15) | (15) | (15)
Atrophy | | 2 (13%) | | 1 (7%) | 3 (20%)
Hyperplasia, lymphoid | | 1 (7%)
Integumentary System
Mammary gland | (15) | (15) | (15) | (15) | (15)
Hyperplasia | | | | 1 (7%)
Skin | (15) | (15) | (15) | (15) | (15)
Subcutaneous tissue, edema | | | | | 1 (7%)
Musculoskeletal System
Bone | (15) | (15) | (15) | (15) | (15)
Hyperostosis | | | | 1 (7%)
Nervous System
Brain | (15) | (15) | (15) | (15) | (15)
Cerebellum, gliosis | | | | | 1 (7%)
Cerebellum, neuronopathy | | | | 1 (7%) | 3 (20%)
Cerebrum, cyst epithelial inclusion | | | | | 1 (7%)
Cerebrum, hemorrhage | | | | 1 (7%)
Medulla, gliosis | | | | | 2 (13%)
Medulla, neuronopathy | | | | | 3 (20%)
Thalamus, gliosis | | | | | 1 (7%)
Thalamus, neuronopathy | | | | | 3 (20%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Inflammation | 8 (53%) | 8 (53%) | 7 (47%) | 5 (33%) | 3 (20%)
Inflammation, granulomatous | 1 (7%)
Alveolar epithelium, hyperplasia, focal | 1 (7%) | 2 (13%) | 1 (7%) | | 1 (7%)
Arteriole, inflammation, acute | 1 (7%)
Bronchus, foreign body | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, lymphoid | | 1 (7%)
Metaplasia, osseous | | | | | 1 (7%)
Nephropathy | 12 (80%) | 12 (80%) | 10 (67%) | 14 (93%) | 9 (60%)
Renal tubule, accumulation, hyaline droplet | | | 2 (13%) | 1 (7%) | 3 (20%)
Urinary bladder | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion