# REFERENCES

The Aldrich Library of Infrared Spectra (1981). 3rd ed. (C.J. Pouchert, Ed.), Spectrum 1471C. Aldrich Chemical Company Inc., Milwaukee, WI.
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Vol. 1, Spectrum 2:1006B. Aldrich Chemical Company, Inc., Milwaukee, WI.
American Hospital Formulary Service (AHFS) (1995). AHFS Drug Information^®^ 95 (G. K. McEvoy, Ed.), pp. 1986–1995. American Society of Health-System Pharmacists, Bethesda, MD.
Bergan, T., Fotland, M.H., and Sund, R.B. (1982). Interaction between diphenolic laxatives and intestinal bacteria in vitro. Acta Pharmacol. Toxicol. (Copenh.) 51, 165–172.6896788
Biondi, O., Andreozzi, L., Amoruso, S., and Motta, S. (2000). Phenolphthalein induces chromosome aberrations in human and Chinese hamster liver cells (CHEL) cultured in vitro. Teratog. Carcinog. Mutagen. 20, 209–217.10910471
Bishop, J.B., Morris, R.W., Seely, J.C., Hughes, L.A., Cain, K.T., and Generoso, W.M. (1997). Alterations in the reproductive patterns of female mice exposed to xenobiotics. Fundam. Appl. Toxicol. 40, 191–204.9441715
Bishop, M.E., Aidoa, A., Damon, O.E., Morris, S.M., and Casciano, D.A. (1998). Phenolphthalein induces micronuclei in transgenic human lymphoblastoid cells. Environ. Mol. Mutagen. 32, 286–288.9814444
Bo-Linn, G.W., Santa Ana, C.A., Morawski, S.G., and Fordtrand, J.S. (1983). Purging and calorie absorption in bulimic patients and normal women. Ann. Intern. Med. 99, 14–17.6190422
Bonin, A.M., Farquharson, J.B., and Baker, R.S.U. (1981). Mutagenicity of arylmethane dyes in salmonella. Mutat. Res. 89, 21–34.6165887
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90 day and 2 year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Code of Federal Regulations (CFR) 21, Part 58.
Code of Federal Regulations (CFR) 21, Part 310.
Colburn, W.A., Hirom, P.C., Parker, R.J., and Milburn, P. (1979). A pharmacokinetic model for enterohepatic recirculation in the rat: Phenolphthalein, a model drug. Drug Metab. Dispos. 7, 100–102.38070
Collins, B.J., Grizzle, T.B., and Dunnick, J.K. (2000). Toxicokinetics of phenolphthalein in male and female rats and mice. Toxicol. Sci. 56, 271–281.10910984
Cooper, G.S., Longnecker, M.P., and Peters, R.K. (2004). Ovarian cancer risk and use of phenolphthalein-containing laxatives. Pharmacoepidemiol. Drug Saf. 13, 35–39.14971121
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Cross, S.M., Sanchez, C.A., Morgan, C.A., Schimke, M.K., Ramel, S., Idzerda, R.L., Raskind, W.H., and Reid, B.J. (1995). A p53-dependent mouse spindle checkpoint. Science 267, 1353–1356.7871434
Cummings, J.H. (1974). Laxative abuse. Gut 15, 758–766.4435592
Dietz, D.D., Elwell, M.R., Chapin, R.E., Shelby, M.D., Thompson, M.B., Filler, R., and Stedham, M.A. (1992). Subchronic (13-week) toxicity studies of oral phenolphthalein in Fischer 344 rats and B_6_C_3_F_1_ mice. Fundam. Appl. Toxicol. 18, 48–58.1601209
Dixon, W.J., and Massey, F.J., Jr. (1957). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunnick, J.K., Hardisty, J.F., Herbert, R.A., Seely, J.C., Furedi-Machacek, E.M., Foley, J.F., Lacks, G.D., Stasiewicz, S., and French, J.E. (1997). Phenolphthalein induces thymic lymphomas accompanied by loss of the p53 wild type allele in heterozygous p53-deficient (±) mice. Toxicol. Pathol. 25, 533–540.9437796
EPA/NIH Mass Spectral Data Base (1978). p. 2434, U.S. Government Printing Office, Washington, DC.
Fairburn, C.G., and Cooper, P.J. (1984). Binge-eating, self-induced vomiting and laxative abuse: A community study. Psychol. Med. 14, 401–410.6588399
Fang, Y., Liu, T., Wang, X., Yang, Y.-M., Deng, H., Kunicki, J., Traganos, F., Darzynkiewicz, Z., Lu, L., and Dai, W. (2006). BubR1 is involved in regulation of DNA damage responses. Oncogene 25, 3598–3605.16449973
Fantus, B., and Dyniewicz, J.M. (1937). Phenolphthalein studies. A thousand doses of phenolphthalein: Urinalyses. JAMA 108, 439–443.
Federal Register (1975). Food and Drug Administration Over-The-Counter Drugs. Proposal to establish monographs for OTC laxative, antidiarrheal, emetic and antiemetic products. Vol. 40, pp. 12,901–12,944.
French, J., Storer, R.D., and Donehower, L.A. (2001a). The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol. Pathol. 29, 24–29.11695559
French, J.E., Lacks, G.D., Trempus, C., Dunnick, J.K., Foley, J., Mahler, J., Tice, R.R., and Tennant, R.W. (2001b). Loss of heterozygosity frequency at the Trp53 locus in p53-deficient (+/–) mouse tumors is carcinogen and tissue-dependent. Carcinogenesis 22, 99–106.11159747
French, J.E., Lacks, G.D., Trempus, C., Dunnick, J.K., Foley, J., Mahler, J., Tice, R.R., and Tennant, R.W. (2002). Loss of heterozygosity frequency at the Trp53 locus in p53-deficient (+/–) mouse tumors is carcinogen-and tissue-dependent (Erratum). Carcinogenesis 23, 373.
Fujita, H., Mizuo, A., and Hiraga, K. (1976). Mutagenicity of dyes in the microbial system. Annu. Rep. Tokyo Metr. Res. Lab. P.H. 27, 153–158.
Garner, C.E., Burka, L.T., Etheridge, A.E., and Matthews, H.B. (2000a). Catechol metabolites of polychlorinated biphenyls inhibit the catechol-O-methyltransferase-mediated metabolism of catechol estrogens. Toxicol. Appl. Pharmacol. 162, 115–123.10637135
Garner, C.E., Matthews, H.B., and Burka, L.T. (2000b). Phenolphthalein metabolite inhibits catechol-O-methyltransferase-mediated metabolism of catechol estrogens: A possible mechanism for carcinogenicity. Toxicol. Appl. Pharmacol. 162, 124–131.10637136
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Goodman and Gilman’s The Pharmacological Basis of Therapeutics (1990). 8th ed. (A.G. Gilman, T.W. Rall, A.S. Nies, and P. Taylor, Eds.), pp. 920–924. Pergamon Press, Inc., New York.
Griffin, R.J., Godfrey, V.B., and Burka, L.T. (1998). Metabolism and disposition of phenolphthalein in male and female F344 rats and B6C3F1 mice. Toxicol. Sci. 42, 73–81.9579019
Halmi, K.A., Falk, J.R., and Schwartz, E. (1981). Binge-eating and vomiting: A survey of a college population. Psychol. Med. 11, 697–706.6948315
Heizer, W.D., Warshaw, A.L., Waldmann, T.A., and Laster, L. (1968). Protein-losing gastroenteropathy and malabsorption associated with factitious diarrhea. Ann. Intern. Med. 68, 893–852.
Holden, H.E. (1998). Phenolphthalein: A sheep in wolf’s clothing? Environ. Mol. Mutagen. 31, 103–104.9544187
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Hubacher, M.H. (1945). Solubility, density and melting point of phenolphthalein. J. Am. Pharm. Assoc. 34, 76–78.
Hulla, J.E., French, J.E., and Dunnick, J.K. (2001a). Chromosome 11 allelotypes reflect a mechanism of chemical carcinogenesis in heterozygous p53-deficient mice. Carcinogenesis 22, 89–98.11159746
Hulla, J.E., French, J.E., and Dunnick, J.K. (2001b). Chromosome 11 loss from thymic lymphomas induced in heterozygous Trp53 mice by phenolphthalein. Toxicol. Sci. 60, 264–270.11248138
Imaoka, M., Kashida, Y., Watanabe, T., Ueda, M., Onodera, H., Hirose, M., and Mitsumori, K. (2002). Tumor promoting effect of phenolphthalein on development of lung tumors induced by N-ethyl-N-nitrosourea in transgenic mice carrying human prototype c-Ha-ras gene. J. Vet. Med. Sci. 64, 489–493.12130832
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC 27707.
International Agency for Research on Cancer (IARC) (2000). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Some Industrial Chemicals, Vol. 77. IARC, Lyon, France.
Johnson, C.L., Stuckey, M.K., Lewis, L.D., and Schwartz, D.M. (1982). Bulimia: A descriptive survey of 316 cases. Int. J. Eat. Disord. 2, 3–16.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Jondorf, W.R., Maickel, R.P., and Brodie, B.B. (1958). Inability of newborn mice and guinea pigs to metabolize drugs. Biochem. Pharmacol. 1, 352–354.
Kada, T., Tutikawa, K., and Sadaie, Y. (1972). In vitro and host-mediated “rec-assay” procedures for screening chemical mutagens; and phloxine, a mutagenic red dye detected. Mutat. Res. 16, 165–174.4342303
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Koujitani, T., Yasuhara, K., Usui, T., Nomura, T., Onodera, H., Takagi, H., Hirose, M., and Mitsumori, K. (2000). Lack of susceptibility of transgenic mice carrying the human c-Ha-ras proto-oncogene (rasH2 mice) to phenolphthalein in a 6-month carcinogenicity study. Cancer Lett. 152, 211–216.10773414
Kurokawa, K., Tanaka, T., and Kato, J.-Y. (1999). p19^ARF^ prevents G1 cyclin-dependent kinase activation by interacting with MDM2 and activating p53 in mouse fibroblasts. Oncogene 18, 2718–2727.10348346
LaRusso, N.F., and McGill, D.B. (1975). Surreptitious laxative ingestion. Mayo Clin. Proc. 50, 706–708.1195781
Longnecker, M.P., Sandler, D.P., Haile, R.W., and Sandler, R.S. (1997). Phenolphthalein-containing laxative use in relation to adenomatous colorectal polyps in three studies. Environ. Health Perspect. 105, 1210–1212.9370521
Lowe, S.W., and Sherr, C.J. (2003). Tumor suppression by INK4a/Arf: Progress and puzzles. Curr. Opin. Genet. Dev. 13, 77–83.12573439
Lucier, G.W., and McDaniel, O.S. (1977). Steroid and non-steroid UDP glucuronyltransferase: Glucuronidation of synthetic estrogens as steroids. J. Steroid Biochem. 8, 867–872.413009
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Mason, R.W., Simpson-Small, T., and Hopp, L. (2003). Regulation of ^86^Rb^+^ ion transport across polarized human colonocytes by bis-phenolic compounds. Clin. Exp. Pharmacol. Physiol. 30, 623–626.12940878
Mason, R.W., Hopp, L., and Lloyd, J.B. (2004). Nitric oxide does not mediate promotion of cellular potassium release by phenolphthalein in COS-7 cells. Clin. Exp. Pharmacol. Physiol. 31, 271–273.15053826
Meek, D.W. (2000). The role of p53 in the response to mitotic spindle damage. Pathol. Biol. (Paris) 48, 246–254.10858957
Mehendale, H.M. (1990). Assessment of hepatobiliary function with phenolphthalein and phenolphthalein glucuronide. Clin. Chem. Enzyme Commun. 2, 195–204.
The Merck Index (1989). 11th ed. (S. Budavari, Ed.), pp. 1150–1151. Merck and Company, Rahway, NJ.
The Merck Index (1996). 12th ed. (S. Budavari, Ed.), p. 1248. Merck & Company, Whitehouse Station, NJ.
Millburn, P., Smith, R.L., and Williams, R.T. (1967). Biliary excretion of foreign compounds. Biphenyl, stilboestrol and phenolphthalein in the rat: Molecular weight, polarity and metabolism as factors in biliary excretion. Biochem. J. 105, 1275–1281.16742556
Mitchell, J.E., Pyle, R.L., Eckert, E.D., Hatsukami, D., and Lentz, R. (1983). Electrolyte and other physiological abnormalities in patients with bulimia. Psychol. Med. 14, 273–278.
Morrison, D.F. (1976). Multivariate Statistical Methods, 2nd ed., pp. 170–179. McGraw-Hill Book Company, New York.
Mortelmans, K., Haworth, S., Lawlor, T., Speck, W., Tainer, B., and Zeiger, E. (1986). Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ. Mutagen. 8 (Suppl. 7), 1–119.
National Center for Biotechnology Information (NCBI) (2005). Unigene, http://www.ncbi.nlm.nih.gov/entrez/query.fcgi?CMD=search&DB=unigene.
National Toxicology Program (NTP) (1986). Toxicology and Carcinogenesis Studies of Benzene (CAS No. 71-43-2) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 289. NIH Publication No. 86-2545. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1990). Toxicology and Carcinogenesis Studies of Glycidol (CAS No. 556-52-5) in F344/N Rats and B6C3F_1_ Mice. Technical Report Series No. 374. NIH Publication No. 90-2829. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1996). Toxicology and Carcinogenesis Studies of Phenolphthalein (CAS No. 77-09-8) in F344/N Rats and B6C3F_1_ Mice (Feed Studies). Technical Report Series No. 465. NIH Publication No. 97-3390. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2004). Report on Carcinogens, 11th ed., pp. III-214–III-216. U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology and Carcinogenesis Study of Benzene (CAS No. 71-43-2) in Genetically Modified Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Gavage Study). GMM Report Series No. 8. NIH Publication No. 08-4425. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007b). Toxicology and Carcinogenesis Study of Glycidol (CAS No. 556-52-5) in Genetically Modified Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Gavage Study). GMM Report Series No. 13. NIH Publication No. 08-5962. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Okamura, M., Kashida, Y., Watanabe, T., Yasuhara, K., Onodera, H., Hirose, M., Usui, T., Tamaoki, N., Mitsumori, K. (2003). Lack of susceptibility of heterozygous p53-knockout CBA and CIEA mice to phenolphthalein in a 6-month carcinogenicity study. Toxicology 185, 17–22.12505441
Parker, R.J., Hirom, P.C., and Millburn, P. (1980). Enterohepatic recycling of phenolphthalein, morphine, lysergic acid diethylamide (LSD) and diphenylacetic acid in the rat. Hydrolysis of glucuronic acid conjugates in the gut lumen. Xenobiotica 10, 689–703.7445530
Pietrusko, R.G. (1977). Use and abuse of laxatives. Am. J. Hosp. Pharm. 34, 291–300.324272
Pohl, A., and Lowe, J.P. (1978). Phenolphthalein poisoning — four cases. Proc. Mine Med. Off. Assoc. S.A. 57, 84–86.
Pyle, R.L., Mitchell, J.E., and Eckert, E.D. (1981). Bulimia: A report of 34 cases. J. Clin. Psychiatry 42, 60–64.6936397
Quelle, D.E., Zindy, F., Ashmun, R.A., and Sherr, C.J. (1995). Alternative reading frames of the INK4a tumor suppressor gene encode two unrelated proteins capable of inducing cell cycle arrest. Cell 83, 993–1000.8521522
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Ravdin, P.M., van Beurden, M., and Jordan, V.C. (1987). Estrogenic effects of phenolphthalein on human breast cancer cells in vitro. Breast Cancer Res. Treat. 9, 151–154.3620717
Sax’s Dangerous Properties of Industrial Materials (1992). 8th ed. (R.J. Lewis, Ed.), p. 2730. Van Nostrand Reinhold, New York.
Schwartz, D., and Rotter, V. (1998). p53-Dependent cell cycle control: Response to genotoxic stress. Semin. Cancer Biol. 8, 325–336.10101798
Serrano, M., Hannon, G.J., and Beach, D. (1993). A new regularity motif in cell-cycle control causing specific inhibition of cyclin D/CDK4. Nature 366, 704–707.8259215
Serrano, M., Lee, H., Chin, L., Cordon-Cardo, C., Beach, D., and DePinho, R.A. (1996). Role of the INK4a locus in tumor suppression and cell mortality. Cell 85, 27–37.8620534
Shapiro, G.I., Edwards, C.D., Ewen, M.E., and Rollins, B.J. (1998). p16^INK4A^ participates in a G_1_ arrest checkpoint in response to DNA damage. Mol. Cell Biol. 18, 378–387.9418885
Shapiro, G.I., Edwards, C.D., and Rollins, B.J. (2000). The physiology of p16^INK4A^-mediated G1 proliferative arrest. Cell Biochem. Biophys. 33, 189–197.11325039
Sharaiha, Z.K., Sackman, J.W., and Graham, D.Y. (1983). Comparison of phenolphthalein and phenolphthalein glucuronide on net water transport in rat ileum and colon. Dig. Dis. Sci. 28, 827–832.6884169
Sharpless, N.E. (2005). INK4a/ARF: A multifunctional tumor suppressor locus. Mutat. Res. 576, 22–38.15878778
Sharpless, N.E., and DePinho, R.A. (1999). The INK4A/Arf locus and its two gene products. Curr. Opin. Genet. Dev. 9, 22–30.10072356
Sherr, C.J., and McCormick, F. (2002). The RB and p53 pathways in cancer. Cancer Cell 2, 103–112.12204530
Sherr, C.J., and Weber, J.D. (2000). The Arf/p53 pathway. Curr. Opin. Genet. Dev. 10, 94–99.10679383
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Sipe, H.J., Jr., Corbett, J.T., and Mason, R.P. (1997). In vitro free radical metabolism of phenolphthalein by peroxidases. Drug Metab. Dispos. 25, 468–480.9107547
Stoll, R.E., Blanchard, K.T., Stoltz, J.H., Majeska, J.B., Furst, S., Lilly, P.D., and Mennear, J.H. (2006). Phenolphthalein and bisacodyl: Assessment of genotoxic and carcinogenic responses in heterozygous p53 (+/–) mice and Syrian hamster embryo (SHE) assay. Toxicol. Sci. 90, 440–450.16373391
Stout, T.J., Tondi, D., Rinaldi, M., Barlocco, D., Pecorari, P., Santi, D.V., Kuntz, I.D., Stroud, R.M., Shoichet, B.K., and Costi, M.P. (1999). Structure-based design of inhibitors specific for bacterial thymidylate synthase. Biochemistry 38, 1607–1617.9931028
Sund, R.B., and Hillestad, B. (1982). Uptake, conjugation and transport of laxative diphenols by everted sacs of the rat jejunum and stripped colon. Acta Pharmacol. Toxicol. (Copenh.) 51, 377–387.6897480
Sund, R.B., and Lauterbach, F. (1986). Drug metabolism and metabolite transport in the small and large intestine: Experiments with 1-naphthol and phenolphthalein by luminal and contraluminal administration in the isolated guinea pig mucosa. Acta Pharmacol. Toxicol. (Copenh.) 58, 74–83.3953296
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tice, R.R., Furedi-Machacek, M., Satterfield, D., Udumudi, A., Vasquez, M., and Dunnick, J.K. (1998). Measurement of micronucleated erythrocytes and DNA damage during chronic ingestion of phenolphthalein in transgenic female mice heterozygous for the p53 gene. Environ. Mol. Mutagen. 31, 113–124.9544189
Tsutsui, T., Tamura, Y., Yagi, E., Hasegawa, K., Tanaka, Y., Uehama, A., Someya, T., Hamaguchi, F., Yamamoto, H., and Barrett, J.C. (1997). Cell-transforming activity and genotoxicity of phenolphthalein in cultured Syrian hamster embryo cells. Int. J. Cancer 73, 697–701.9398048
Van Rooyen, R.J., and Ziady, F. (1972). Hypokalaemic alkalosis following the abuse of purgatives. S. Afr. Med. J. 46, 998–1003.5055940
Velentzas, C.G., and Ikkos, D.G. (1971). Phenolphthalein as cause of factitious enteritis. JAMA 217, 966.
Visek, W.J., Liu, W.C., and Roth, L.J. (1956). Studies on the fate of carbon-14 labeled phenolphthalein. J. Pharmacol. Exp. Ther. 117, 347–357.13332581
Weast, R.C., Ed. (1987). CRC Handbook of Chemistry and Physics, p. C-416. CRC Press, Inc., Boca Raton, FL.
Weber, J.D., Taylor, L.J., Roussel, M.F., Sherr, C.J., and Bar-Sagi, D. (1999). Nucleolar Arf sequesters Mdm2 and activates p53. Nat. Cell Biol. 1, 20–26.10559859
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Wishart, G.J. (1978a). Functional heterogeneity of UDP-glucuronosyltransferase as indicated by its differential development and inducibility by glucocorticoids: Demonstration of two groups within the enzyme’s activity towards twelve substrates. Biochem. J. 174, 485–489.101211
Wishart, G.J. (1978b). Demonstration of functional heterogeneity of hepatic uridine diphosphate glucuronosyltransferase activities after administration of 3-methylcholanthrene and phenobarbital to rats. Biochem. J. 174, 671–672.101214
Witt, K.L., Gulati, D.K., Kaur, P., and Shelby, M.D. (1995). Phenolphthalein: Induction of micronucleated erythrocytes in mice. Mutat. Res. 341, 151–160.7529356
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 26, 163–194.