# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On August 28, 2006, the draft Report on the toxicology and carcinogenesis study of phenolphthalein received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. J.K. Dunnick, NIEHS, introduced the study of phenolphthalein in haploinsufficient p16^Ink4a^/p19^Arf^ mice by reviewing the uses of the chemical as a laxative, the previous NTP carcinogenicity findings, the design and dose selection for the genetically modified mouse model studies, and the nonneoplastic lesions observed in the 27-week study. The proposed conclusions were no evidence of carcinogenic activity of phenolphthalein in male or female haploinsufficient p16^Ink4a^/p19^Arf^ mice.

Dr. Deininger, the first principal reviewer, noted that the dose selection was based on the 2-year study and suggested that possibly doses could have been higher in this study.

Dr. Walker, the second principal reviewer, had no additional comments.

Dr. Sikka, the third principal reviewer, suggested that in discussion of the role of p53, apoptosis as well as cell cycle arrest should be mentioned.

Dr. Walker suggested that the following statement be added to the conclusion, because no neoplastic effects were seen in this study:

Because this is a new model, there is uncertainty whether this study possessed sufficient sensitivity to detect a carcinogenic effect.

Dr. Deininger moved, and Dr. Soper seconded, that the conclusions be accepted with this addition. The motion was approved unanimously with seven votes.