# NATIONAL TOXICOLOGY PROGRAM BOARD OF SCIENTIFIC COUNSELORS TECHNICAL REPORTS REVIEW SUBCOMMITTEE

The members of the Technical Reports Review Subcommittee who evaluated the draft NTP Report on phenolphthalein on August 28, 2006, are listed below. Subcommittee members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, subcommittee members have five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

- Charlene A. McQueen, Ph.D., Chairperson
  College of Pharmacy
  University of Arizona
  Tucson, AZ
- Diane F. Birt, Ph.D.
  Department of Food Science and Human Nutrition
  Iowa State University
  Ames, IA
- Christopher Bradfield, Ph.D.^*^
  McArdle Laboratory for Cancer Research
  University of Wisconsin
  Madison, WI
- Kenny Crump, Ph.D.^*^
  Environ International
  Ruston, LA
- Prescott Deininger, Ph.D., Principal Reviewer
  Tulane University Medical Center
  New Orleans, LA
- John P. Giesy, Jr., Ph.D.
  Department of Zoology
  Michigan State University
  East Lansing, MI
- Nancy Kerkvliet, Ph.D.^*^
  Department of Environmental and Molecular Toxicology
  Oregon State University
  Corvallis, OR
- Jon Mirsalis, Ph.D.
  SRI International
  Menlo Park, CA
- Harish Sikka, Ph.D., Principal Reviewer
  Environmental Toxicology and Chemistry Laboratory
  State University of New York College at Buffalo
  Buffalo, NY
- Keith Soper, Ph.D.
  Merck Research Laboratories
  West Point, PA
- Vernon Walker, D.V.M., Ph.D., Principal Reviewer
  Lovelace Respiratory Institute
  Albuquerque, NM

* Did not attend