# DISCUSSION AND CONCLUSIONS

Phenolphthalein is a bisphenolic compound that was used as a laxative for most of the 20th century. NTP studies have shown that phenolphthalein exposure causes carcinogenic effects in F344/N rats and B6C3F_1_ mice after a 2-year exposure period and in haploinsufficient p53 mice after a 6-month exposure period (NTP, 1996; Dunnick et al., 1997).

No treatment-related neoplasms were identified in this study. However, a putative precursor lesion, atypical hyperplasia of the thymus, occurred at increased incidences in exposed haploinsufficient p16^Ink4a^/p19^Arf^ female (9/74) and male (2/73) mice. Haploinsufficient p16^Ink4a^/p19^Arf^ mice remain relatively free of spontaneous tumors at 8 months of age, the time frame in which this study was completed. However, by 11 months of age (Appendix G), tumors including malignant lymphoma begin to occur spontaneously. Atypical hyperplasia of the thymus is an uncommon lesion in mice and reported in only a few strains, including B6.129-p53 deficient (N5) and B6C3F_1_ mice. Atypical hyperplasia of lymphocytes and/or malignant lymphoma involving the thymus were induced by phenolphthalein in haploinsufficient p53 and B6C3F_1_ mice (NTP, 1996; Dunnick et al., 1997) and by benzene in haploinsufficient p16^Ink4a^/p19^Arf^ mice (NTP, 2007a). The cases of atypical hyperplasia of the thymus occurring in exposed haploinsufficient p16^Ink4a^/p19^Arf^ mice in this study were morphologically similar to those previously described. Since atypical hyperplasia is considered a premalignant change of chemically induced thymic lymphoma (Dunnick, et al., 1997), it is possible that with more time, some cases of atypical hyperplasia in this study may have evolved into malignant lymphoma.

Phenolphthalein was negative in the Salmonella mutagenicity assay (NTP, 1996), but it has been shown to induce micronucleated erythrocytes in a number of studies in different strains of mice (Dietz et al., 1992; Witt et al., 1995; Tice et al., 1998; Stoll et al., 2006). Although significant increases in the frequencies of micronucleated erythrocytes were seen at each of four sampling time points in the 6-month study with phenolphthalein-exposed haploinsufficient p16^Ink4a^/p19^Arf^ mice, the response was diminished compared with the magnitude of the response induced by phenolphthalein in haploinsufficient p53 (Tice et al., 1998; Figure 4) or B6C3F_1_ mice (Dietz et al., 1992). The majority of chemicals that induce micronuclei in mice in vivo have been shown to be rodent carcinogens (Witt et al., 2000), and phenolphthalein was carcinogenic in both haploinsufficient p53 and B6C3F_1_ mice.

Exposure of haploinsufficient p53 mice to phenolphthalein in the diet induced an exposure concentration-related increase in the incidence of lymphoma and highly significant increases in the frequency of micronucleated erythrocytes (Dunnick et al., 1997; Tice et al., 1998; Figure 4). In haploinsufficient p16^Ink4a^/p19^Arf^ mice in the present study, phenolphthalein induced increased incidences of atypical hyperplasia in the thymus and small but significant increases in micronucleated erythrocytes (Figure 4). It may be that the duration of the present study was insufficient to detect an increase in the incidences of lymphoma in this mouse model, or the magnitude of the difference in the micronucleus response between the two mouse models [haploinsufficient p16^Ink4a^/p19^Arf^ (80% C57Bl/6 background) and haploinsufficient p53 (97% C57Bl/6 background)] is biologically significant and predictive of the tumor response.

Ink4a inhibits Cdk4/Cdk6 and phosphorylation of Rb resulting in G1/S arrest in response to DNA damage (Shapiro et al., 1998, 2000). Thus, p16^Ink4a^ deficiency compromises the ability to arrest the cell cycle in response to direct DNA damage and repair. A decrease in Arf may allow Mdm2 to bind more readily to p53, allowing for degradation of p53, and suppression of p53’s ability to promote G1/S arrest and induce apoptosis and mitotic spindle checkpoint functions (Kurokawa et al., 1999; Weber et al., 1999). The indirect effect on p53 function may not be as critical to maintaining cell function when it is mediated through loss of p19^Arf^ function in this mouse model as direct loss of p53 function in the p53 haploinsufficient mouse. Thus, the haploinsufficiency in the p16^Ink4a^/p19^Arf^ deficient mouse compromises both the Ink4a-Rb and the Arf-p53 signaling pathways and, thus, affects both the G1/S cell cycle checkpoint through p16^Ink4a^ regulation of Rb and p19^Arf^ regulation of p53 through Mdm2 and, to a lesser extent, the mitotic spindle checkpoints in response to DNA and mitotic spindle damage through Arf-p53.

FIGURE 4 Micronucleus Results Comparison Between Haploinsufficient p16^Ink4a^/p19^Arf^ Male and Female Mice and Haploinsufficient p53 Female Mice Exposed to Phenolphthalein

The p53 tumor suppressor protein is critical for both the G1/S cell cycle and apoptosis and mitotic spindle checkpoint functions, and loss of p53 function may increase aneuploidy (non-disjunction and chromosome duplication) by failing to resolve anaphase bridges (centromere division) (Cross et al., 1995; Schwartz and Rotter, 1998; Meek, 2000; Fang et al., 2006). The observed magnitude of the difference in micronuclei and the specific induction of kinetechore positive micronuclei in the phenolphthalein studies in the haploinsufficient p53 mouse may be explained by the critical role of p53 in the mitotic spindle checkpoint and prevention of phenolphthalein-induced aneuploidy (Tice et al., 1998). Thus, the mode of action of phenolphthalein-induced DNA and chromosomal damage that results in non-disjunction and aneuploidy may be less influenced by the p16-RB and p19Arf-p53 pathway functions than the p53 function, and/or differences in genetic composition may explain the biological differences observed between these two mouse models.

In the current study, phenolphthalein induced other toxic effects in the haploinsufficient p16^Ink4a^/p19^Arf^ mouse including nephropathy and reproductive toxicity in male mice. Phenolphthalein-induced toxicity to the male reproductive system has previously been observed in B6C3F_1_ mice after 13-week and 2-year exposures (NTP, 1996). In the current haploinsufficient p16^Ink4a^/p19^Arf^ mouse study, phenolphthalein induced male target organ toxicity at 3,000 or 12,000 ppm, as demonstrated by lower epididymis and testis weights and decreased sperm motility and numbers at 12,000 ppm. In the 13-week B6C3F_1_ mouse study, lower epididymal weights and sperm density were seen at doses of 12,000 ppm or greater (NTP, 1996). In the 2-year B6C3F_1_ mouse study, degeneration of the testis was seen in all exposed groups (3,000, 6,000, and 12,000 ppm). In a continuous breeding protocol, phenolphthalein caused lower fertility in CD-1 mice at concentrations of 700 ppm or greater (NTP, 1996).

Phenolphthalein administered in the feed for 2 years induced significant increases in the incidences of histiocytic sarcoma and lymphoma of thymic origin in male and female B6C3F_1_ mice; malignant lymphoma and benign ovarian sex cord stromal tumors in female B6C3F_1_ mice; benign pheochromocytomas of the adrenal medulla in male and female F344/N rats; and renal tubule adenoma in male F344/N rats (NTP, 1996). Phenolphthalein induced thymic lymphomas in haploinsufficient p53 female mice (Dunnick et al., 1997). Phenolphthalein induced preneoplastic lesions in the thymus of haploinsufficient p16^Ink4a^/p19^Arf^ mice in the current study.

## Conclusions

Under the conditions of this 27-week feed study, there was no evidence of carcinogenic activity^*^ of phenolphthalein in male or female haploinsufficient p16^Ink4a^/p19^Arf^ mice exposed to 200, 375, 750, 3,000, or 12,000 ppm. Because this is a new model, there is uncertainty whether the study possessed sufficient sensitivity to detect a carcinogenic effect.

Phenolphthalein induced atypical hyperplasia, a preneoplastic lesion of the thymus, in male and female mice, hematopoietic cell proliferation of the spleen in male and female mice, and toxicity to the kidney and reproductive system in male mice.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 8. A summary of the Technical Report Review Subcommittee comments and the public discussion on this Report appears on page 10.