# RESULTS

## Mice 27-Week Study

### Survival

Estimates of 27-week survival probabilities for male and female mice are shown in Table 3. Survival of all exposed groups of male and female mice was similar to that of the control groups.

### Body Weights, Feed and Compound Consumption, Organ Weights, Clinical Findings, and Sperm Evaluation

Mean body weights of males in the 12,000 ppm group were less than those of the control group after week 11 (Figure 3 and Table 4). Mean body weights of exposed females were similar to those of the control group throughout the study (Figure 3 and Table 5). No differences in feed consumption were noted between exposed and control groups (Tables F1 and F2). Dietary concentrations of 200, 375, 750, 3,000, and 12,000 ppm delivered average daily doses of approximately 35, 65, 135, 540, and 2,170 mg/kg to males and 50, 90, 170, 680, and 2,770 mg/kg to females. No clinical findings related to phenolphthalein exposure were observed in males or females.

No exposure-related changes in organ weights were observed for females (Table C1). Compared to the control group, the absolute and relative right and left testis weights of 3,000 and 12,000 ppm males were significantly less (Tables C1 and D1). The left epididymis and left testis weights of 3,000 and 12,000 ppm males and the left cauda epididymis weight of 12,000 ppm males were significantly less than those of the controls.

In 12,000 ppm males, sperm motility and the numbers of spermatid heads per testis and sperm heads per cauda and per gram cauda epididymis were significantly less than those of the control groups; except for motility, these parameters were also significantly less in the 3,000 ppm group.

TABLE 3 Survival of Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 1 | 0 | 0 | 0 | 0 | 0
Natural deaths | 1 | 0 | 0 | 2 | 0 | 1
Animals surviving to study termination | 13 | 15 | 15 | 13 | 15 | 14
Percent probability of survival at end of study^a^ | 87 | 100 | 100 | 87 | 100 | 93
Mean survival (days)^b^ | 165 | 183 | 183 | 163 | 183 | 173
Survival analysis^c^ | P=1.000N | P=0.464N | P=0.464N | P=1.000 | P=0.464N | P=0.984N
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 1 | 0 | 0 | 0
Natural deaths | 0 | 2 | 0 | 0 | 1 | 0
Animals surviving to study termination | 15 | 13 | 14 | 15 | 14 | 15
Percent probability of survival at end of study | 100 | 87 | 93 | 100 | 93 | 100
Mean survival (days) | 184 | 162 | 173 | 184 | 174 | 184
Survival analysis | P=0.746N | P=0.464 | P=1.000 | —^d^ | P=1.000 | —

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

d Value of statistic cannot be computed.

FIGURE 3 Growth Curves for Male and Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice Exposed to Phenolphthalein in Feed for 27 Weeks

TABLE 4 Mean Body Weights and Survival of Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

Weeks on Study | 0 ppm | | 200 ppm | | | 375 ppm | | | 750 ppm | | | 3,000 ppm | | | 12,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.1 | 15 | 20.0 | 100 | 15 | 19.9 | 99 | 15 | 20.0 | 100 | 15 | 19.9 | 99 | 15 | 19.6 | 98 | 15
2 | 21.0 | 15 | 21.0 | 100 | 15 | 20.7 | 99 | 15 | 20.9 | 100 | 15 | 20.8 | 99 | 15 | 20.8 | 99 | 15
3 | 21.4 | 15 | 21.6 | 101 | 15 | 20.9 | 98 | 15 | 20.8 | 97 | 15 | 21.1 | 99 | 15 | 20.6 | 96 | 15
4 | 22.4 | 14 | 21.8 | 97 | 15 | 21.5 | 96 | 15 | 21.6 | 96 | 14 | 21.5 | 96 | 15 | 20.8 | 93 | 15
5 | 22.8 | 14 | 22.9 | 100 | 15 | 22.6 | 99 | 15 | 22.2 | 97 | 14 | 22.4 | 98 | 15 | 22.0 | 97 | 15
6 | 23.8 | 14 | 23.5 | 99 | 15 | 23.5 | 99 | 15 | 23.3 | 98 | 14 | 23.3 | 98 | 15 | 22.6 | 95 | 14
7 | 24.5 | 14 | 24.6 | 100 | 15 | 23.9 | 98 | 15 | 24.4 | 100 | 13 | 24.1 | 98 | 15 | 23.6 | 96 | 14
8 | 25.4 | 14 | 25.5 | 100 | 15 | 24.8 | 98 | 15 | 25.4 | 100 | 13 | 25.0 | 98 | 15 | 24.2 | 95 | 14
9 | 25.8 | 14 | 26.4 | 102 | 15 | 25.4 | 98 | 15 | 25.9 | 100 | 13 | 25.0 | 97 | 15 | 24.8 | 96 | 14
10 | 25.9 | 14 | 26.6 | 103 | 15 | 25.2 | 97 | 15 | 26.2 | 101 | 13 | 25.9 | 100 | 15 | 25.0 | 97 | 14
11 | 26.9 | 14 | 27.3 | 102 | 15 | 26.2 | 97 | 15 | 26.8 | 100 | 13 | 26.8 | 100 | 15 | 25.6 | 95 | 14
12 | 27.0 | 13 | 28.0 | 104 | 15 | 26.8 | 99 | 15 | 27.5 | 102 | 13 | 27.0 | 100 | 15 | 25.4 | 94 | 14
13 | 27.8 | 13 | 28.2 | 101 | 15 | 27.1 | 98 | 15 | 27.9 | 100 | 13 | 27.1 | 98 | 15 | 26.2 | 94 | 14
14 | 28.9 | 13 | 29.0 | 100 | 15 | 28.4 | 98 | 15 | 29.3 | 101 | 13 | 28.2 | 98 | 15 | 26.8 | 93 | 14
15 | 29.4 | 13 | 29.5 | 100 | 15 | 28.7 | 98 | 15 | 29.8 | 101 | 13 | 28.8 | 98 | 15 | 26.9 | 92 | 14
16 | 30.5 | 13 | 31.1 | 102 | 15 | 29.9 | 98 | 15 | 30.1 | 99 | 13 | 29.8 | 98 | 15 | 27.7 | 91 | 14
17 | 30.4 | 13 | 31.0 | 102 | 15 | 29.2 | 96 | 15 | 30.5 | 100 | 13 | 29.6 | 97 | 15 | 28.4 | 93 | 14
18 | 31.8 | 13 | 32.0 | 101 | 15 | 30.9 | 97 | 15 | 30.9 | 97 | 13 | 30.0 | 94 | 15 | 28.2 | 89 | 14
19 | 32.6 | 13 | 32.1 | 99 | 15 | 31.4 | 96 | 15 | 31.9 | 98 | 13 | 29.8 | 91 | 15 | 28.5 | 87 | 14
20 | 32.4 | 13 | 32.8 | 101 | 15 | 32.0 | 99 | 15 | 32.1 | 99 | 13 | 31.1 | 96 | 15 | 28.9 | 89 | 14
21 | 33.0 | 13 | 33.1 | 100 | 15 | 32.5 | 99 | 15 | 32.4 | 98 | 13 | 31.9 | 97 | 15 | 28.6 | 87 | 14
22 | 33.7 | 13 | 33.7 | 100 | 15 | 33.3 | 99 | 15 | 34.3 | 102 | 13 | 32.4 | 96 | 15 | 29.7 | 88 | 14
23 | 34.0 | 13 | 34.2 | 101 | 15 | 34.1 | 100 | 15 | 33.8 | 99 | 13 | 32.1 | 94 | 15 | 29.3 | 86 | 14
24 | 34.1 | 13 | 34.8 | 102 | 15 | 34.6 | 102 | 15 | 34.3 | 101 | 13 | 32.9 | 97 | 15 | 29.8 | 87 | 14
25 | 35.2 | 13 | 35.6 | 101 | 15 | 35.2 | 100 | 15 | 35.1 | 100 | 13 | 32.8 | 93 | 15 | 30.4 | 86 | 14
26 | 34.3 | 13 | 36.0 | 105 | 15 | 35.4 | 103 | 15 | 35.9 | 105 | 13 | 33.6 | 98 | 15 | 30.3 | 88 | 14
Mean for weeks
1–13 | 24.2 | | 24.4 | 101 | | 23.7 | 98 | | 24.1 | 99 | | 23.8 | 98 | | | 23.2 | 96
14–27 | 32.3 | | 32.7 | 101 | | 32.0 | 99 | | 32.3 | 100 | | 31.0 | 96 | | | 28.7 | 89

TABLE 5 Mean Body Weights and Survival of Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

Weeks on Study | 0 ppm | | 200 ppm | | | 375 ppm | | | 750 ppm | | | 3,000 ppm | | | 12,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 16.4 | 15 | 16.4 | 100 | 15 | 16.4 | 100 | 15 | 16.5 | 101 | 15 | 16.5 | 101 | 15 | 16.5 | 101 | 15
2 | 17.8 | 15 | 17.4 | 98 | 15 | 17.6 | 99 | 15 | 17.8 | 100 | 15 | 18.0 | 101 | 15 | 17.7 | 99 | 15
3 | 18.7 | 15 | 17.8 | 95 | 14 | 18.2 | 97 | 14 | 17.9 | 96 | 15 | 18.2 | 97 | 15 | 18.6 | 100 | 15
4 | 19.0 | 15 | 18.5 | 97 | 13 | 18.7 | 98 | 14 | 18.6 | 98 | 15 | 18.5 | 97 | 15 | 19.1 | 101 | 15
5 | 19.8 | 15 | 19.3 | 98 | 13 | 19.8 | 100 | 14 | 19.4 | 98 | 15 | 19.8 | 100 | 14 | 19.8 | 100 | 15
6 | 20.8 | 15 | 20.4 | 98 | 13 | 19.9 | 96 | 14 | 20.6 | 99 | 15 | 20.8 | 100 | 14 | 20.9 | 101 | 15
7 | 21.3 | 15 | 20.9 | 98 | 13 | 21.2 | 100 | 14 | 21.0 | 99 | 15 | 21.4 | 101 | 14 | 21.6 | 101 | 15
8 | 21.8 | 15 | 21.9 | 101 | 13 | 21.8 | 100 | 14 | 22.0 | 101 | 15 | 22.0 | 101 | 14 | 22.0 | 101 | 15
9 | 22.2 | 15 | 22.1 | 100 | 13 | 22.4 | 101 | 14 | 22.2 | 100 | 15 | 21.7 | 98 | 14 | 22.2 | 100 | 15
10 | 22.4 | 15 | 21.6 | 96 | 13 | 22.4 | 100 | 14 | 22.0 | 98 | 15 | 22.0 | 98 | 14 | 22.5 | 100 | 15
11 | 22.1 | 15 | 22.3 | 101 | 13 | 23.3 | 105 | 14 | 22.3 | 101 | 15 | 22.3 | 101 | 14 | 23.2 | 105 | 15
12 | 22.5 | 15 | 22.4 | 100 | 13 | 23.1 | 103 | 14 | 22.5 | 100 | 15 | 22.7 | 101 | 14 | 23.1 | 103 | 15
13 | 22.7 | 15 | 23.0 | 101 | 13 | 23.4 | 103 | 14 | 23.1 | 102 | 15 | 22.8 | 100 | 14 | 23.4 | 103 | 15
14 | 23.4 | 15 | 23.1 | 99 | 13 | 23.8 | 102 | 14 | 23.1 | 99 | 15 | 23.1 | 99 | 14 | 23.5 | 100 | 15
15 | 22.9 | 15 | 23.1 | 101 | 13 | 23.4 | 102 | 14 | 23.1 | 101 | 15 | 22.7 | 99 | 14 | 23.6 | 103 | 15
16 | 23.7 | 15 | 23.5 | 99 | 13 | 24.2 | 102 | 14 | 23.5 | 99 | 15 | 23.6 | 100 | 14 | 23.9 | 101 | 15
17 | 23.6 | 15 | 23.8 | 101 | 13 | 23.8 | 101 | 14 | 24.1 | 102 | 15 | 24.1 | 102 | 14 | 24.0 | 102 | 15
18 | 24.0 | 15 | 23.8 | 99 | 13 | 24.4 | 102 | 14 | 24.2 | 101 | 15 | 24.0 | 100 | 14 | 24.1 | 100 | 15
19 | 24.5 | 15 | 24.4 | 100 | 13 | 24.7 | 101 | 14 | 24.6 | 100 | 15 | 24.4 | 100 | 14 | 24.5 | 100 | 15
20 | 24.5 | 15 | 25.0 | 102 | 13 | 25.1 | 102 | 14 | 24.8 | 101 | 15 | 24.7 | 101 | 14 | 25.0 | 102 | 15
21 | 24.7 | 15 | 24.8 | 100 | 13 | 25.0 | 101 | 14 | 24.5 | 99 | 15 | 24.3 | 98 | 14 | 24.7 | 100 | 15
22 | 24.4 | 15 | 25.6 | 105 | 13 | 24.6 | 101 | 14 | 25.4 | 104 | 15 | 25.2 | 103 | 14 | 24.9 | 102 | 15
23 | 24.2 | 15 | 24.8 | 103 | 13 | 25.6 | 106 | 14 | 24.3 | 100 | 15 | 24.6 | 102 | 14 | 25.6 | 106 | 15
24 | 24.8 | 15 | 25.0 | 101 | 13 | 25.4 | 102 | 14 | 25.5 | 103 | 15 | 25.2 | 102 | 14 | 25.5 | 103 | 15
25 | 25.6 | 15 | 25.6 | 100 | 13 | 26.4 | 103 | 14 | 25.1 | 98 | 15 | 25.3 | 99 | 14 | 25.4 | 99 | 15
26 | 25.3 | 15 | 25.5 | 101 | 13 | 26.5 | 105 | 14 | 25.1 | 99 | 15 | 25.1 | 99 | 14 | 25.4 | 100 | 15
Mean for weeks
1–13 | 20.6 | | 20.3 | 99 | | 20.6 | 100 | | 20.5 | 99 | | 20.5 | 100 | | 20.8 | 101
14–27 | 24.3 | | 24.5 | 101 | | 24.8 | 102 | | 24.4 | 101 | | 24.3 | 100 | | 24.6 | 101

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions in the thymus, testis, epididymis, kidney, and spleen. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A1, A2, A3, and A4.

Thymus: Atypical hyperplasia was observed in 375, 3,000, and 12,000 ppm females, and the incidence in 12,000 ppm females was significantly greater than that in the controls (Tables 6 and A4). One 375 ppm male and one 3,000 ppm male had atypical hyperplasia (Tables 6 and A2). This lesion was characterized by the presence of a thymic lobule that had a moderate cell density, loss of corticomedullary organizational distinction, and sheets of large lymphocytes or other mononuclear cells. Atypical hyperplasia of the thymus has been described in B6C3F_1_ and p53 deficient mice (Dunnick et al., 1997) and characterized as a distinct proliferation of large, immature lymphocytes confined to one or both lobes of the thymus accompanied by an absence of distinct thymic corticomedullary junction. Often the affected lobe(s) were smaller than normal, and the lymphocytes did not extend beyond the thymic capsule. Atypical hyperplasia is sometimes preceded by thymic atrophy and believed to be a premalignant change of chemically-induced thymic lymphoma.

Testis and epididymis: Significantly increased incidences of atrophy of the seminiferous tubules and coinciding hyperplasia of the testicular interstitial (Leydig) cells and epididymal hypospermia occurred in 3,000 and 12,000 ppm males (Tables 6 and A2). Testis atrophy was characterized by smaller testis profiles, decreased numbers of germinal epithelial cells, individualization or separation of germinal epithelial cells, vacuolization of germinal epithelial cell cytoplasm, and syncytial cell formation. The epididymis from affected testicles had hypospermia (decrease intraluminal sperm) with decreased lumen profiles. The lumens sometimes contained desquamated germinal epithelial cells and increased hyaline protein.

Kidney: Significantly increased incidences of minimal to mild nephropathy occurred in 3,000 and 12,000 ppm males, and the severity was slightly increased in the 12,000 ppm group (Tables 6 and A2). Nephropathy was consistent with the spontaneous condition described in various mouse strains and characterized by cortical foci of regenerative tubular epithelium (basophilic tubules with nuclear crowding) with varying degrees of chronic interstitial inflammation and fibrosis, tubular dilation, tubular epithelial cell atrophy, protein casts, desquamated renal tubular epithelium, and eosinophilic tubular debris.

There were increased incidences of minimal hypertrophy of renal tubules in the 750 ppm or greater male groups. Hypertrophy of renal tubules was characterized as occasional, scattered individual or clusters of enlarged tubular epithelium. Hypertrophy is an uncommon lesion in rodents that is sometimes observed as part of advanced nephropathy (which was not evident in this study) and not considered a preneoplastic or proliferative change (G. Hard, personal communication). In this setting, it was likely an adaptive physiological response, possibly related to altered sodium ion exchange.

Spleen: Significantly increased incidences of hematopoietic cell proliferation occurred in 12,000 ppm males and 375, 750, and 12,000 ppm females (Tables 6, A2, and A4). Increased numbers of hematopoietic cells, primarily erythroid series, composed the hematopoietic cell proliferation. Most instances were graded as minimal and consisted of increased cell density with no increase in splenic size. A few mice had slightly higher severity grades sometimes accompanied by an increased overall size of the splenic profile.

## Genetic Toxicology

The frequency of micronucleated normochromatic erythrocytes (NCEs) was assessed in male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice at 6.5, 13, 19.5, and 27 weeks of exposure to phenolphthalein. At all four time points, a significant increase in micronucleated NCEs was observed in both sexes (Table B1). At the 6.5-week sampling time, the mean micronucleus frequencies of the two highest exposure groups (3,000 and 12,000 ppm) of males and females were significantly increased over the controls (Table B1). The trend test was positive (P<0.001). At all subsequent sampling times, only the 12,000 ppm groups showed significant increases in micronucleated NCEs compared to the controls. No significant alterations in the percentage of polychromatic erythrocytes were seen in male or female mice at any sampling time, indicating an absence of phenolphthalein-induced toxicity to the bone marrow.

TABLE 6 Incidences of Selected Nonneoplastic Lesions in Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Male
Thymus^a^ | 14 | 15 | 15 | 14 | 15 | 14
Hyperplasia, Atypical^b^ | 0 | 0 | 1 (2.0)^c^ | 0 | 1 (3.0) | 0
Testes | 15 | 15 | 15 | 15 | 15 | 15
Germinal Epithelium, Atrophy | 0 | 1 (1.0) | 1 (4.0) | 0 | 15^**^ (1.6) | 14^**^ (2.6)
Interstitial Cell, Hyperplasia | 0 | 1 (1.0) | 1 (2.0) | 0 | 15^**^ (1.5) | 14^**^ (1.8)
Epididymis | 15 | 15 | 15 | 15 | 15 | 15
Hypospermia | 0 | 0 | 1 (4.0) | 0 | 15^**^ (1.1) | 14^**^ (3.0)
Kidney | 14 | 15 | 15 | 14 | 15 | 15
Nephropathy | 6 (1.0) | 7 (1.0) | 8 (1.0) | 6 (1.0) | 15^**^ (1.0) | 14^**^ (1.4)
Renal Tubule, Hypertrophy | 0 | 0 | 0 | 10^**^ (1.0) | 15^**^ (1.0) | 14^**^ (1.0)
Spleen | 14 | 15 | 15 | 14 | 15 | 14
Hematopoietic Cell Proliferation | 2 (1.0) | 5 (1.4) | 3 (2.0) | 1 (1.0) | 2 (1.0) | 14^**^ (1.0)
Female
Thymus | 15 | 15 | 15 | 15 | 14 | 15
Hyperplasia, Atypical | 0 | 0 | 1 (3.0) | 0 | 3 (2.0) | 5^*^ (2.6)
Spleen | 15 | 14 | 14 | 15 | 15 | 15
Hematopoietic Cell Proliferation | 2 (1.0) | 5 (1.0) | 9^**^ (1.1) | 8^*^ (1.0) | 7 (1.3) | 13^**^ (1.0)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked