# MATERIALS AND METHODS

## Procurement and Characterization of Phenolphthalein

Phenolphthalein was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (13427LF). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC), Galbraith Laboratories, Inc. (Knoxville, TN), and the study laboratory, Battelle Columbus Operations (Columbus, OH) (Appendix E). Reports on analyses performed in support of the phenolphthalein study are on file at the National Institute of Environmental Health Sciences.

The chemical, a light brown/yellowish-white powder, was identified as phenolphthalein by the analytical chemistry laboratory using direct probe mass spectrometry and infrared, ultraviolet/visible, and proton nuclear magnetic resonance spectroscopy and by the study laboratory using infrared spectroscopy. The melting point range was consistent with a literature value (Merck, 1989).

The moisture content of lot 13427LF was determined by Galbraith Laboratories, Inc., using Karl Fischer titration; this laboratory also performed elemental analyses of lot 13427LF. The purity of lot 13427LF was determined by the analytical chemistry laboratory and by the study laboratory using high-performance liquid chromatography (HPLC). For lot 13427LF, Karl Fischer titration indicated 0.507% water. Elemental analyses for carbon, hydrogen, and oxygen were consistent with the theoretical values for phenolphthalein. HPLC analyses indicated one major peak and one impurity of 0.4%. The overall purity of lot 13427LF was determined to be greater than 99%.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using HPLC. These studies indicated that phenolphthalein was stable as a bulk chemical for at least 14 days when stored protected from light at temperatures up to 60° C. To ensure stability, the bulk chemical was stored in the original shipping containers at room temperature, protected from light. Stability was monitored during the study using HPLC; no degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately every 4 weeks by mixing phenolphthalein with feed (Table E2). A premix was prepared by hand and then blended with additional feed in a Patterson-Kelley twin-shell blender for 15 minutes using an intensifier bar for the initial 5 minutes. Formulations were stored in plastic buckets at −20° C or below for up to 42 days, with the exception of formulations prepared on November 29, 1999, which were originally stored at room temperature for 2 days and then transferred to −20° C storage.

Homogeneity studies of the 200 and 12,000 ppm dose formulations were performed by the analytical chemistry and study laboratories using HPLC. Stability studies of the 200 ppm dose formulation were performed by the analytical chemistry laboratory using HPLC. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed glass bottles protected from light at −20° C and for at least 7 days under simulated animal room conditions (exposed to light and air) in the absence of animal excreta.

Periodic analyses of the dose formulations of phenolphthalein were conducted by the study laboratory using HPLC. All 15 dose formulations analyzed and used in the study were within 10% of the target concentrations; the dose formulations prepared on November 29, 1999, were not adversely affected by storage at room temperature for 2 days (Table E3). Animal room samples of these dose formulations were also analyzed; two of five animal room samples were within 10% of the target concentrations. Degradation was attributed to unavoidable excreta in the feeders.

## 27-Week Study

### Study Design

Groups of 15 male and 15 female mice were fed diets containing 0, 200, 375, 750, 3,000, or 12,000 ppm phenolphthalein for 27 weeks. The exposure concentrations selected for use in the 27-week phenolphthalein study were chosen to overlap those used for p53^+/–^ mice in a phenolphthalein feed study (Dunnick et al., 1997) and for B6C3F_1_ mice in a 2-year feed study of phenolphthalein (NTP, 1996).

### Source and Specification of Animals

Male and female heterozygous B6.129-Cdkn2a^tm1Rdp^ N2 (i.e., haploinsufficient p16^Ink4a^/p19^Arf^) mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY) for use in the 27-week study. The N1 male mice homozygous null for the Cdkn2a deletion were backcrossed to inbred C57BL/6 females from Taconic Laboratory to produce male and female B6.129-Cdkn2^atm1Rdp^ haploinsufficient or p16^Inka^/p19^Arf+/–^ mice (Serrano et al., 1996). The genetic background of these mice was: 80% C57BL/6, 19% 129/Sv, and 1% SJL. This line, designated 5003 by Taconic Laboratory, was embryo cryopreserved in 2003. Upon receipt, the mice were 4 weeks old. Animals were quarantined for 14 days and were 6 weeks old on the first day of the study. Before the study began, five male and five female mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood samples were collected from four male and four female sentinel animals at 5 weeks and at study termination. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative.

### Animal Maintenance

Mice were housed individually. Feed and water were available ad libitum. Cages and racks were rotated every 2 weeks. Further details of animal maintenance are given in Table 2.

### Clinical Examinations and Pathology

All mice were observed twice daily. Clinical findings were recorded weekly. The mice were weighed initially, weekly, and at the end of the study.

At the end of the 27-week study, samples were collected from all male mice for sperm motility evaluations. The parameters evaluated are listed in Table 2. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Modified Tyrode’s buffer was applied to slides, and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65° C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. Histopathologic examinations were performed on all mice. Table 2 lists the tissues and organs routinely examined.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified; and the histotechnique was evaluated. For the 27-week study, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the epididymis, kidney, ovary, spleen, testis, and thymus.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) chairperson, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the chairperson to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

TABLE 2 Experimental Design and Materials and Methods in the 27-Week Feed Study of Phenolphthalein

Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Heterozygous B6.129-Cdkn2a^tm1Rdp^ N3)
Animal Source
Taconic Laboratory Animals and Services (Germantown, NY)
Time Held Before Study
14 days
Average Age When Studies Began
6 weeks
Date of First Exposure
December 8, 1999
Duration of Exposure
7 days/week for 27 weeks
Date of Last Exposure
June 7–9, 2000
Necropsy Dates
June 7–9, 2000
Average Age at Necropsy
32 to 33 weeks
Size of Study Groups
15 males and 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo and ear tag
Diet
Irradiated NTP-2000 pelleted feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Maywood, NJ), changed weekly
Racks
Stainless steel (Lab Products, Inc., Maywood, NJ), changed every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly
Cage Filters
DuPont 2024 spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3° F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour
Exposure Concentrations
0, 200, 375, 750, 3,000, or 12,000 ppm in feed, available ad libitum
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, weekly, and at the end of the study; clinical findings were recorded weekly.
Method of Sacrifice
CO_2_ asphyxiation
Necropsy
Necropsies were performed on all animals. Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus.
Histopathology
Histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, large intestine (colon, cecum, rectum), small intestine (duodenum, ileum, jejunum), heart, kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, ovary, pituitary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, urinary bladder, and uterus.
Sperm Motility
At the end of the study, sperm samples were collected from all male mice for sperm motility evaluations. Spermatid and sperm measurements were evaluated. The left cauda, left epididymis, and left testis were weighed.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958). Animals found dead of other than natural causes were censored from the survival analyses; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A2, A3, and A4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test, a procedure based on the overall proportion of affected animals, was used to determine significance (Gart et al., 1979).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Spermatid and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) (as modified by Williams, 1986) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1957) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973). Treatment effects were investigated by applying a multivariate analysis of variance (Morrison, 1976) to the transformed data to test for simultaneous equality of measurements across exposure concentrations.

## Quality Assurance Methods

The 27-week study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records were submitted to the NTP Archives, this study was audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At 6.5, 13, 19.5, and 27 weeks, peripheral blood samples were obtained from male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of up to 15 animals per dose group. In addition, the percentage of polychromatic erythrocytes among 1,000 total erythrocytes was determined for each animal as a measure of phenolphthalein-induced bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the interim samplings and the final sample at 27 weeks were accepted without repeat tests, because additional test data were not available. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.