# INTRODUCTION

PHENOLPHTHALEIN

CAS No. 77-09-8

Chemical Formula: C_20_H_14_O_4_ Molecular Weight: 318.33

Synonyms: 3,3-Bis(4-hydroxyphenyl)-1(3H)-isobenzofuranone; 3,3-bis(p-hydroxyphenyl)phthalide; α-(p-hydroxyphenyl)-α-(4-oxo-2,5-cyclohexadien-1-ylidene)-o-toluic acid

Trade names: Agoral^®^, Alophen^®^, Colax^®^, Correctol^®^, Dialose^®^, Doxidan^®^, Espotabs^®^, Evac-U-Gen^®^, Evac-U-Lax^®^, Ex-Lax^®^, Feen-A-Mint^®^, FemiLax^®^, Kondremul^®^, LaxCaps^®^, Lax-Pills^®^, Medilax^®^, Modane^®^, Phenolax^®^, Prulet^®^

## Chemical and Physical Properties

Phenolphthalein is a white or yellowish white, odorless, tasteless powder consisting of minute triclinic crystals (often twinned). It has a specific gravity of 1.277 at 32/4° C and a melting point range of 262° to 273° C (Weast, 1987) or 258° to 262° C (Merck, 1996), depending on the relative amounts of associated impurities. Although not flammable, phenolphthalein emits acrid smoke and fumes when heated to decomposition (Sax’s, 1992). Phenolphthalein is readily soluble in alcohol (1 g dissolves in 12 to 15 mL) or ether (1 g dissolves in approximately 100 mL) and very slightly soluble in chloroform. It is almost insoluble in water; however, its solubility is increased in physiologic buffered solutions simulating intestinal contents, i.e., 7.8 mg/dL in Krebs-Ringer-bicarbonate solution, pH 7.4 (Sharaiha et al., 1983). The solubility of aqueous phenolphthalein is also pH dependent and does not exceed 6 mg/dL without the addition of ethanol until the pH is above the physiologic range, i.e., greater than 9 (Fantus and Dyniewicz, 1937; Hubacher, 1945). Solutions containing phenolphthalein are colorless to pH 8.5 and pink to deep red above pH 9. Phenolphthalein is used as a laboratory reagent and an acid-base indicator in titrations of mineral and organic acids and most alkalies (Merck, 1996).

## Production, Use, and Human Exposure

Phenolphthalein was commonly used as a laxative for most of the 20th century. In 1997, only one company produced phenolphthalein in the United States, but there were 39 suppliers of phenolphthalein in the United States. The use of phenolphthalein in laxatives has decreased since 1997 when the United States Food and Drug Administration (FDA) proposed to withdraw its classification as an over-the-counter drug (21 CFR, Part 310). In 1997, the makers of Ex-Lax^®^ announced that they were reformulating their laxative using senna instead of phenolphthalein. The major route of human exposure to phenolphthalein is via ingestion, dermal contact, and inhalation of contaminated air originating from process units manufacturing the compound (NTP, 2004).

When phenolphthalein was available as an over-the-counter laxative, the usual daily oral laxative doses for white or yellow phenolphthalein were 30 to 270 mg for adults and children 12 years of age and older, 30 to 60 mg for children 6 to 11 years of age, and 15 to 30 mg for children 2 to 5 years of age, although the use of stimulant laxatives is generally not recommended in children younger than 6 years of age (Fed. Regist., 1975; AHFS, 1995).

In making its final rule on phenolphthalein, the FDA was concerned about the improper uses of the over-the-counter laxative by the public. Laxative-cathartics, such as phenolphthalein, are habit forming (i.e., chronic usage resulting in dependence), are commonly used to self-medicate symptoms of constipation, and are frequently abused in an effort to control weight (Pietrusko, 1977; Goodman and Gilman’s, 1990). Ten percent of college students who participated in a 1981 survey admitted to purging behavior, i.e., laxative use and self-induced vomiting (Halmi et al., 1981). Purging behavior is also associated with the eating disorders anorexia nervosa and bulimia nervosa; laxative abuse has been reported in 38% to 63% of bulimia nervosa patients (Van Rooyen and Ziady, 1972; Pyle et al., 1981; Johnson et al., 1982; Bo-Linn et al., 1983; Mitchell et al., 1983; Fairburn and Cooper, 1984). A review by Cummings (1974) indicated that over 90% of chronic laxative abusers are women.

## Regulatory Status

The final United States FDA rule removed phenolphthalein as an over-the-counter drug in 1999 (21 CFR, Part 310).

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Metabolism of phenolphthalein in animals is similar to that in humans (NTP, 1996; Griffin et al., 1998; Collins et al., 2000; Figure 1). The drug is absorbed from the gastrointestinal tract, and the major metabolite is phenolphthalein glucuronide (PTH-G), which undergoes enterohepatic recirculation. A catechol metabolite of phenolphthalein, hydroxyphenolphthalein (PT-CAT), has been identified (Garner et al., 2000a,b). These authors hypothesize that PT-CAT inhibits the enzyme catechol-O-methyltransferase (COMT) and, therefore, potentiates genotoxicity by either PT-CAT itself or the endogenous catechol estrogens in susceptible tissues. The concentration of uridine diphosphate glucuronosyltransferase (UDPGT; the enzyme responsible for phenolphthalein conjugation) is low in fetal or neonatal rodent tissue compared to that in the adult. Metabolism of phenolphthalein in p53^+/–^ mice is similar to that in B6C3F_1_ mice (Collins et al., 2000).

Phenolphthalein is absorbed from the intestine and is excreted in the bile, urine, feces, and milk (Visek et al., 1956; AHFS, 1995). Once phenolphthalein is absorbed, it is conjugated with glucuronic acid via UDPGT in the liver and intestine (Sund and Hillestad, 1982) and is distributed throughout the body in the blood and lymph (Visek et al., 1956). Studies reported in the literature provide evidence for enzyme multiplicity of UDPGT. Steroidal and nonsteroidal UDPGT may have different membrane environments, and certain tissues such as the kidney and uterus have been shown to have a lower UDPGT activity for xenobiotic estrogenic compounds such as phenolphthalein (Lucier and McDaniel, 1977). Minor amounts of sulfate conjugate metabolites have also been detected in mucosal sheets isolated from the jejunum and colon of the guinea pig (Sund and Lauterbach, 1986).

FIGURE 1 Metabolic Scheme for [^14^C]-Phenolphthalein in F344/N Rats and B6C3F_1_ Mice (Griffin et al., 1998)

Phenolphthalein conjugation enzyme activity UDPGT is absent or very low in microsomes from fetal or neonatal rat and guinea pig liver compared to activity from adult livers (Jondorf et al., 1958; Wishart, 1978a). Glucuronide conjugation activity in adult rats is stimulated by phenobarbital and unaffected by 3-methylcholanthrene (Wishart, 1978b).

Pharmacokinetic and tissue distribution studies in mice (strain not specified) and dogs (breed not specified) given 4.8 mg [^14^C]-phenolphthalein/kg (uniformly labeled) indicated that phenolphthalein was widely and evenly distributed throughout the body, with levels of radioactivity parallel to the concentration in the blood. In dogs, approximately 50% of an oral dose was recovered in the feces and 36% in the urine after 72 hours (Visek et al., 1956).

In the mouse studies (Visek et al., 1956), no respiratory [^14^C]-carbon dioxide was recovered following administration of phenolphthalein labeled with ^14^C on the non-aromatic carbon of the lactone ring, indicating that the bonds to the labeled carbon atoms probably were not broken. Within 48 hours, approximately 96% of the administered radioactivity was recovered in the urine and feces (56% in the urine and 38% in the feces following an oral dose; 30% in the urine and 68% in the feces following an intravenous dose). At 30 minutes to 6 hours, the highest levels of radioactivity appeared in the liver, gallbladder, and small intestine. On a total organ basis, the small intestine, which plays a major role in the excretion of phenolphthalein, contained more radioactive label than did the large intestine at all measurement intervals. However, when equated on a unit weight basis, the radioactivity of the large intestine and its contents increased substantially 6 hours after dosing.

Phenolphthalein undergoes extensive first pass metabolism in the intestinal epithelium and liver, which results in almost complete conversion of phenolphthalein to its glucuronide (Parker et al., 1980). Studies by Colburn et al. (1979) demonstrated that 6 hours after intravenous administration of [^3^H]-phenolphthalein to female Wistar rats, all radioactivity in the systemic circulation was present as the conjugate. In addition, a secondary peak in blood radioactivity occurred 5 to 6 hours after intravenous administration and coincided with the absorption of [^3^H]-phenolphthalein from the intestine following bacterial β-glucuronidase hydrolysis of [^3^H]-phenolphthalein glucuronide excreted in the bile. Hydrolysis of phenolphthalein glucuronide to the aglycone is a rate-limiting step in enterohepatic recirculation (Bergan et al., 1982); pretreatment with antibiotics to suppress intestinal microflora decreased the absorption of [^3^H]-phenolphthalein from 85% to 22% in female Wistar rats following intraduodenal administration of [^3^H]-phenolphthalein glucuronide (Parker et al., 1980).

Phenolphthalein has been used as a model compound for enterohepatic recirculation studies in rats (Colburn et al., 1979), and surgical cannulation of the bile duct has been used to evaluate the extent of enterohepatic recirculation in rats and dogs. In bile duct-cannulated female Wistar rats, 95% of an intraperitoneal dose of 25 mg [^3^H]-phenolphthalein/kg was recovered in the bile as the glucuronide within 24 hours, while only 0.2% was recovered in the urine. Administration of the same dose to intact rats resulted in recovery of 86% in the feces, predominantly as the parent drug, and 10% in the urine as the glucuronide (Parker et al., 1980). In another study in female Wistar rats with biliary fistulae, phenolphthalein was completely eliminated in the bile (100%), almost entirely in the form of phenolphthalein glucuronide (98%) (Millburn et al., 1967). The plasma disappearance and excretion kinetics of phenolphthalein glucuronide in the rat have been characterized in Mehendale (1990). Male Sprague-Dawley rats of the CR-1 strain were intravenously administered 3, 30, or 60 mg phenolphthalein or 3, 30, or 100 mg phenolphthalein glucuronide, and the femoral vein, artery, and common bile duct were cannulated. After administration of phenolphthalein, 99.5% of the dose was eliminated in the bile as phenolphthalein glucuronide with only trace quantities (0.5%) as phenolphthalein. Following administration of phenolphthalein glucuronide, phenolphthalein was undetectable in the bile. Biliary excretion was saturable at higher doses of both compounds.

### Humans

Phenolphthalein is absorbed from the small intestine and conjugated in the liver to phenolphthalein glucuronide (PTH-G). PTH-G is excreted in bile and passes into the colon where the glucuronide is hydrolyzed by bacterial flora. In humans, approximately 70% to 90% of an ingested dose is eliminated in the feces in the free or conjugated form, and renal excretion accounts for the remaining 10% to 30% of the dose in the free or conjugated form (NTP, 1996; Collins et al., 2000).

## Toxicity

### Experimental Animals

The toxicity of phenolphthalein has been summarized by the National Toxicology Program (1996) and the International Agency for Research on Cancer (2000). Phenolphthalein is not acutely toxic in rodents. In 13-week toxicity studies in F344/N rats and B6C3F_1_ mice (NTP, 1996), where animals were exposed to up to 50,000 ppm in the feed, there was no treatment-related mortality or clinical signs of toxicity or gross or microscopic lesions in rats. In mice, hypoplasia of the bone marrow occurred at exposures of 12,000 ppm or greater. This lesion was characterized by decreased amounts of hematopoietic tissue with a decreased myeloid to erythroid ratio. Splenic hematopoiesis was seen in male mice exposed to 25,000 ppm or greater. There was no evidence of a laxative effect for phenolphthalein in rats or mice.

### Humans

Phenolphthalein, a drug used for most of the 20th century, was generally regarded as nontoxic and safe at therapeutic doses (approximately 1 to 2 mg/kg) (NTP, 1996; IARC, 2000). Under normal conditions, phenolphthalein has not been associated with acute toxicity in humans. However, indiscriminate use of phenolphthalein results in constipation and laxative dependence. Anecdotal cases of long-term use or overdose of phenolphthalein have been associated with abdominal pain, diarrhea, vomiting, electrolyte imbalance, dehydration, malabsorption, and muscle weakness (Heizer et al., 1968; Velentzas and Ikkos, 1971; Cummings, 1974; LaRusso and McGill, 1975; Pohl and Lowe, 1978; AHFS, 1995).

One hypothesis for the laxative effects of phenolphthalein was by inhibition of the normal water absorption from the bowel, and stimulation of secretion of Na^+^ and Cl^–^ ions accompanied by water excretion (Mason et al., 2003). This phenomenon may be due to inhibition of Na^+^/K^+^-ATPase; recent studies show that nitric oxide generation is not required for phenolphthalein stimulated potassium release (Mason et al., 2004).

## Reproductive and Developmental Toxicity

### Experimental Animals

In the 13-week F344/N rat and B6C3F_1_ mouse studies, there was no evidence for reproductive toxicity in female mice or rats (NTP, 1996). However, lower epididymal weights and sperm density were seen in male mice. In a continuous breeding protocol, phenolphthalein caused lower fertility in mice at levels of 700 ppm and above.

### Humans

There have been no systematic studies to evaluate the reproductive toxicity of phenolphthalein in humans (NTP, 1996; IARC, 2000).

## Carcinogenicity

### Experimental Animals

In the NTP (1996) 2-year study, phenolphthalein was found to be carcinogenic in F344/N rats and B6C3F_1_ mice (Table 1).

Phenolphthalein induced thymic lymphomas in p53^+/–^ mice on a C57BL/6 background (Dunnick et al., 1997). This p53 mouse was the fifth backcross (N5) of p53^–/–^ C57BL/6 males (N4) × inbred wild type C57BL/6 females with a null mutation introduced into a p53 gene by homologous recombination in murine embryonic stem cells by insertion of a neo cassette into the Trp 53 locus resulting in a deletion of a 450-base pair fragment containing 106 nucleotides of exon 5, and about 350 nucleotides of intron 4 (Donehower et al., 1992). The “wild” p53 gene in these phenolphthalein-induced thymic lymphomas was lost (French et al., 2001a,b, 2002; Hulla et al., 2001a,b). The loss of p53 activity and the ability to control the cell cycle and apoptosis were considered to be part of the pathways leading to cancer.

The production of free radicals by phenolphthalein, as demonstrated in in vitro studies, may also take part in the events leading to cancer (Sipe et al., 1997). Phenolphthalein has cell-transforming activity and is genotoxic in Syrian hamster embryo cells (Tsutsui et al., 1997).

When phenolphthalein (3,000, 6,000, or 12,000 ppm in feed) was given alone for 6 months to the rasH2 mouse, no treatment-related tumors were seen (Koujitani et al., 2000). However, in the Imaoka et al. (2002) study with rasH2 mice, 12,000 ppm phenolphthalein administered in the feed for 26 weeks promoted the development of lung tumors induced by N-ethyl-N-nitrosurea (received by intraperitoneal injection of 60 mg/kg body weight). Phenolphthalein (26-week exposure to 6,000 or 12,000 ppm in feed) did not induce tumors in a p53^+/–^ mouse on a CBA or CIEA background, where the p53 gene was knocked out in exon 2 (Okamura, 2003).

### Humans

No studies to adequately evaluate the possible relation between excess consumption of phenolphthalein used in weight control and cancer development have been reported (Bishop et al., 1997). One study found no relationship between phenolphthalein use as a laxative and the development of adenomatous colorectal polyps (Longnecker et al., 1997), and another study found no relationship between phenolphthalein use as a laxative and a risk for ovarian cancer (Cooper et al., 2004).

Phenolphthalein has been shown to cause chromosomal aberrations in human cells (Biondi et al., 2000). Human thymidylate synthase is inhibited by micromolar concentrations of phenolphthalein with an IC_50_ of 1.2 µM. Inhibition of thymine synthesis stops the production of DNA, disrupts progress through the cell cycle, and eventually leads to cell death (Stout et al., 1999).

Phenolphthalein competes with estrogen for binding to cultured MCF-7 human breast cancer cells, with a relative binding affinity 10^−4^ that of estradiol, and it stimulates cell growth as measured by DNA and protein assays (Ravdin et al., 1987). Acting as an estrogen agonist, phenolphthalein induced elevated levels of progesterone receptor in the MCF-7 cells. Growth stimulation by both phenolphthalein and estradiol was blocked by the anti-estrogen, 4-hydroxytamoxifen.

TABLE 1 Chemical-related Neoplasms in NTP Phenolphthalein Studies

| 0 ppm | 12,000 ppm | 25,000 ppm | 50,000 ppm
F344/N Male Rats (2-Year Feed Study; NTP, 1996)
Adrenal Medulla
Benign Pheochromocytoma | 17/50 (34%) | 34/50 (68%) | 34/50 (68%) | 34/50 (68%)
Kidney
Renal Tubule Adenoma (Standard Evaluation) | 0/50 (0%) | 4/50 (8%) | 2/50 (4%) | 6/50 (12%)
(Standard and Extended Evaluations Combined) | 1/50 (2%) | 10/50 (20%) | 15/50 (30%) | 15/50 (30%)
Renal Tubule Adenoma or Carcinoma (Standard Evaluation) | 0/50 (0%) | 5/50 (10%) | 3/50 (6%) | 7/50 (14%)
(Standard and Extended Evaluations Combined) | 1/50 (2%) | 10/50 (20%) | 16/50 (32%) | 16/50 (32%)
F344/N Female Rats (2-Year Feed Study; NTP, 1996)
Adrenal Medulla
Benign Pheochromocytoma | 3/50 (6%) | 11/50 (22%) | 9/50 (18%) | 2/49 (4%)
Benign or Malignant Pheochromocytoma | 3/50 (6%) | 12/50 (24%) | 10/50 (20%) | 2/49 (4%)
| 0 ppm | 3,000 ppm | 6,000 ppm | 12,000 ppm
B6C3F_1_ Male Mice (2-Year Feed Study; NTP, 1996)
Histiocytic Sarcoma | 1/50 (2%) | 3/50 (6%) | 11/50 (22%) | 12/49 (24%)
Malignant Lymphoma (Thymic Origin) | 0/50 (0%) | 4/50 (8%) | 7/50 (14%) | 2/49 (4%)
B6C3F_1_ Female Mice (2-Year Feed Study; NTP, 1996)
Histiocytic Sarcoma | 0/50 (0%) | 2/50 (4%) | 7/50 (14%) | 7/50 (14%)
Malignant Lymphoma (Multiple Organs) | 15/50 (30%) | 28/50 (56%) | 33/50 (66%) | 25/50 (50%)
Malignant Lymphoma (Thymic Origin) | 1/50 (2%) | 9/50 (18%) | 10/50 (20%) | 7/50 (14%)

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Female p53^+/−^ Mice (Feed Study; Dunnick et al., 1997)
Malignant Lymphoma (Thymic Origin) | 0/19 (0%) | 1/20 (5%) | 0/20 (0%) | 2/20 (10%) | 17/20 (85%) | 14/20 (70%)

Phenolphthalein is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity in experimental animals (NTP, 1996, 2004; IARC, 2000).

## Genetic Toxicity

The mutagenicity data for phenolphthalein indicates that the chemical, although not active in bacterial gene mutation assays (Kada et al., 1972; Fujita et al., 1976; Bonin et al., 1981; Mortelmans et al., 1986) does induce chromosomal damage in mammalian cells in vitro when testing occurs in the presence of induced rat liver S9 enzymes (Witt et al., 1995; Bishop et al., 1998). A number of studies have shown induction of micronuclei by phenolphthalein in mammalian cells in vivo. Blood samples obtained from B6C3F_1_ mice at the end of the NTP 13-week toxicity study with phenolphthalein showed significant increases in micronucleated erythrocytes in males and females (Dietz et al., 1992; NTP, 1996).

Short-term micronucleus assays in mouse bone marrow erythrocytes confirmed the ability of the chemical to induce micronuclei (Witt et al., 1995). The data from this series of short-term tests indicated that relatively high doses (greater than 2,000 mg/kg per day for at least 2 days) administered either in feed or by gavage were required to induce an increase in the frequency of micronucleated erythrocytes in B6C3F_1_ mice. Swiss CD-1 mice appeared to be more sensitive to the effects of phenolphthalein, showing significant increases in micronucleated erythrocytes at doses of 120 mg/kg per day administered in the diet (0.1%) for a period of 14 weeks.

Holden (1998) suggested that phenolphthalein might not induce genetic damage through direct interaction with chromosomal structural components, but that the increases in micronuclei observed in some experiments were the consequence of increased erythropoiesis in response to a phenolphthalein-induced low grade chronic anemia. Although higher doses of phenolphthalein, at which increased frequencies of micronucleated cells are observed, are frequently associated with increased normochromatic erythrocyte/polychromatic erythrocyte (PCE/NCE) ratios (indicating enhanced cell proliferation), elevated micronucleus counts are also seen at lower doses in subchronic studies in the absence of detectable alterations in the percentage of PCEs in blood. Therefore, phenolphthalein is capable of inducing micronuclei in erythrocytes in the absence of signs of overt bone marrow toxicity and accelerated erythropoiesis.

Results of NTP-sponsored micronucleus studies in transgenic p53^+/–^ mice showed highly significant increases in micronucleated erythrocytes in peripheral blood of treated females at all doses ranging from 200 to 12,000 ppm after 26 weeks of administration in feed; increases in the percentages of PCEs were noted at 3,000 and 12,000 ppm, but the increases were small, going from a background of 2.12% to a maximum of 3.77% (Tice et al., 1998). More recently, Stoll et al. (2006) also reported significant increases in micronucleated polychromatic erythrocytes in blood samples obtained from male and female p53^+/–^ mice administered phenolphthalein by gavage or in feed for 39 to 183 days. Furthermore, they reported positive results in the in vitro Syrian hamster embryo assay for cell transformation. In the NTP micronucleus studies, immunofluorescent staining techniques were used to gain additional mechanistic information on the origin of the phenolphthalein-induced micronuclei in the p53^+/–^ mice. Staining for the presence of kinetochores in the micronuclei indicated that the majority of the induced micronuclei contained whole chromosomes and probably resulted from aneuploidy events (changes in chromosome number due to mitotic errors). Results of an alkaline Single Cell Gel (Comet) assay with leukocytes and hepatocytes obtained from the p53^+/–^ mice at the termination of the 6-month study were judged to be equivocal, based on inconsistencies in responses obtained at different sample times during the course of the exposure period (Tice et al., 1998).

## Background on Genetically Altered Mice

The CDKN2A genetic locus contains two important tumor suppressor genes located on chromosomes 9, 4, and 5 in the human, mouse, and rat, respectively (NCBI, 2005). The locus is unique in that alternate splice variants produce two different tumor suppressor proteins (Sherr and Weber, 2000; Sherr and McCormick, 2002; Lowe and Sherr, 2003). The p16^Ink4a^ and p19^Arf^ variants have exons 2 and 3 in common but use different exon 1 (alpha and beta). Expression of these two splice variants is conserved across mammalian species. Mouse p19^Arf^ and human p14^ARF^ polypeptides are approximately 50% identical, and mouse p16^Ink4^ and human p16^Ink4a^ proteins are approximately 72% identical (Quelle et al., 1995).

The two proteins translated from the mRNA expressed from CDKN2A are a p16-KDa protein and a p19-KDa protein (or p14-KDa protein in humans) (Serrano et al., 1996). The p16 protein (p16^Ink4a^, inhibitor of kinase 4a) is a cell cycle regulatory protein that binds to cyclin dependent kinase 4 or 6 (CDK4/6) and inhibits the catalytic activity of the CDK/cyclin D complex and the phosphorylation of retinoblastoma protein. Since loss of the normal function of p16^Ink4a^ leads to uncontrolled cell growth, p16 is classified as a tumor suppressor gene (Serrano et al., 1993). The second protein coded, p19^Arf^ (Arf, alternate reading frame), induces G1 arrest and apoptosis. The 19Arf protein binds to MDM2 and neutralizes MDM2 inhibition of p53 (Sherr and Weber, 2000).

The targeted deletion of exons 2 and 3 of the Cdkn2a gene by a homologous recombination resulted in the elimination of both p16^Ink4a^ and p19^Arf^ proteins (Serrano et al., 1996). Homozygous null Cdkn2a^–/–^ (or Cdkn2a^–/–^) mice are viable and fertile (Serrano et al., 1996). On inspection, these animals appear normal until about 2 months of age, but histological analysis of the spleen shows a mild proliferative expansion of the white pulp and the presence of numerous megakaryocytes and lymphoblasts in the red pulp. The p16^–/–^ mice develop tumors at an average age of 29 weeks. Lymphomas and fibrosarcomas are two common types of tumors seen in this Cdkn2a^–/–^ mouse. In contrast, the Cdkn2a^+/–^ mouse does not usually develop any obvious tumors or display compromised health until after 36 weeks (Serrano et al., 1996).

Deletions in the Cdkn2a gene predispose both rodents and humans to cancer at multiple organ sites (Sharpless and DePinho, 1999). The complete loss of Cdkn2a gene(s) function is observed in approximately 10% of small cell lung tumors, 30% of esophageal tumors, 55% of gliomas, 100% of pancreatic tumors, and 20% of head and neck tumors.

Transition from G1 to S phase in the mammalian cell cycle is under complex regulatory control, and one G1-S regulatory pathway involves p16^Ink4a^ protein. P16^Ink4a^ inhibits the cdk4/cyclin D1 complex, preventing cdk4 from phosphorylating pRb, and thus ensuring that pRb maintains G1 arrest. Disruption of this pathway, by p16^Ink4a^ gene mutations, perturbs the cell cycle (Serrano et al., 1993) and in the case of these Cdkn2a genetically altered mice (Serrano et al., 1993) results in more cell proliferation (Figure 2).

Serrano et al. (1996) report that treatment with DMBA and UV light causes an earlier onset of fibrosarcoma and lymphoma in the p16^–/–^ mouse (8 to 10 weeks) and the p16^–/+^ mouse (7 to 20 weeks).

## Study Rationale

The purpose of this phenolphthalein study and the companion benzene and glycidol studies (NTP, 2007a,b) was to determine if a mouse with a deletion at the p16 gene locus (CDKN2), a locus that codes for two tumor suppressor genes, would enable the identification of carcinogenic chemicals in a shorter time frame and with fewer animals than the traditional 2-year NTP cancer study. These three chemicals were all multisite carcinogens in the NTP 2-year bioassays (NTP 1986, 1990, 1996). This study reports the findings from the phenolphthalein study.

FIGURE 2 The Ink4a/Arf Locus

The open reading frames p16^Ink4a^ (in black) and p19^Arf^ (in crosshatch) are shown. Each has a unique first exon that then splices to a common second exon, but in alternate reading frames. P16^Ink4a^ inhibits cdk4/6 activity producing retinoblastoma phosphorylation, which induces cell cycle arrest. P19^Arf^ inhibits MDM2-mediated degradation of p53 (Sharpless, 2005).