# APPENDIX F FEED AND COMPOUND CONSUMPTION IN THE 27-WEEK FEED STUDY OF PHENOLPHTHALEIN

TABLE F1 Feed and Compound Consumption by Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

Weeks | 0 ppm | | 200 ppm | | | 375 ppm | | | 750 ppm | | | 3,000 ppm | | | 12,000 ppm
Weeks | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.0 | 21.0 | 4.0 | 21.0 | 38 | 4.2 | 20.7 | 77 | 4.1 | 20.9 | 146 | 4.1 | 20.8 | 596 | 4.2 | 20.8 | 2,436
3 | 4.1 | 21.4 | 4.1 | 21.6 | 38 | 4.2 | 20.9 | 75 | 3.9 | 20.8 | 142 | 3.9 | 21.1 | 556 | 4.2 | 20.6 | 2,437
4 | 4.2 | 22.4 | 4.0 | 21.8 | 37 | 4.0 | 21.5 | 70 | 4.3 | 21.6 | 150 | 4.2 | 21.5 | 586 | 4.0 | 20.8 | 2,330
5 | 4.0 | 22.8 | 4.4 | 22.9 | 38 | 4.1 | 22.6 | 68 | 4.1 | 22.2 | 138 | 4.2 | 22.4 | 562 | 4.2 | 22.0 | 2,313
6 | 4.0 | 23.8 | 4.2 | 23.5 | 36 | 4.5 | 23.5 | 71 | 4.5 | 23.3 | 143 | 4.4 | 23.3 | 570 | 4.1 | 22.6 | 2,205
7 | 4.2 | 24.5 | 4.3 | 24.6 | 35 | 4.3 | 23.9 | 68 | 4.3 | 24.4 | 134 | 4.1 | 24.1 | 506 | 4.4 | 23.6 | 2,237
8 | 4.4 | 25.4 | 4.6 | 25.5 | 36 | 4.7 | 24.8 | 72 | 4.8 | 25.4 | 142 | 4.5 | 25.0 | 541 | 4.4 | 24.2 | 2,191
9 | 4.4 | 25.8 | 4.8 | 26.4 | 37 | 4.9 | 25.4 | 73 | 4.4 | 25.9 | 127 | 4.6 | 25.0 | 549 | 4.3 | 24.8 | 2,092
10 | 4.5 | 25.9 | 4.7 | 26.6 | 36 | 4.4 | 25.2 | 65 | 4.5 | 26.2 | 130 | 4.5 | 25.9 | 527 | 4.4 | 25.0 | 2,115
11 | 4.6 | 26.9 | 5.0 | 27.3 | 36 | 4.8 | 26.2 | 69 | 4.9 | 26.8 | 137 | 5.0 | 26.8 | 558 | 4.9 | 25.6 | 2,280
12 | 4.7 | 27.0 | 5.0 | 28.0 | 36 | 5.0 | 26.8 | 70 | 5.0 | 27.5 | 136 | 4.7 | 27.0 | 518 | 4.6 | 25.4 | 2,156
13 | 4.6 | 27.8 | 4.8 | 28.2 | 34 | 4.6 | 27.1 | 64 | 4.9 | 27.9 | 133 | 4.4 | 27.1 | 488 | 4.8 | 26.2 | 2,220
14 | 4.6 | 28.9 | 5.0 | 29.0 | 35 | 5.0 | 28.4 | 66 | 5.0 | 29.3 | 128 | 4.9 | 28.2 | 525 | 4.6 | 26.8 | 2,068
15 | 4.7 | 29.4 | 5.1 | 29.5 | 34 | 4.7 | 28.7 | 61 | 4.8 | 29.8 | 121 | 4.9 | 28.8 | 506 | 4.5 | 26.9 | 2,009
16 | 4.6 | 30.5 | 5.0 | 31.1 | 32 | 4.9 | 29.9 | 61 | 4.9 | 30.1 | 123 | 4.9 | 29.8 | 492 | 4.4 | 27.7 | 1,907
17 | 5.0 | 30.4 | 5.1 | 31.0 | 33 | 4.8 | 29.2 | 62 | 5.4 | 30.5 | 132 | 5.3 | 29.6 | 538 | 5.1 | 28.4 | 2,142
18 | 5.4 | 31.8 | 5.3 | 32.0 | 33 | 5.4 | 30.9 | 66 | 5.3 | 30.9 | 130 | 5.4 | 30.0 | 543 | 4.9 | 28.2 | 2,091
19 | 5.3 | 32.6 | 5.4 | 32.1 | 34 | 5.5 | 31.4 | 65 | 5.6 | 31.9 | 133 | 5.5 | 29.8 | 550 | 5.0 | 28.5 | 2,093
20 | 4.9 | 32.4 | 5.3 | 32.8 | 32 | 5.3 | 32.0 | 62 | 5.5 | 32.1 | 129 | 5.8 | 31.1 | 559 | 5.2 | 28.9 | 2,156
21 | 5.3 | 33.0 | 5.3 | 33.1 | 32 | 5.2 | 32.5 | 60 | 5.7 | 32.4 | 132 | 5.6 | 31.9 | 529 | 5.1 | 28.6 | 2,136
22 | 5.2 | 33.7 | 5.8 | 33.7 | 34 | 5.4 | 33.3 | 61 | 5.8 | 34.3 | 127 | 6.0 | 32.4 | 552 | 5.2 | 29.7 | 2,102
23 | 5.5 | 34.0 | 5.6 | 34.2 | 33 | 5.7 | 34.1 | 63 | 5.8 | 33.8 | 128 | 5.9 | 32.1 | 554 | 5.4 | 29.3 | 2,232
24 | 5.4 | 34.1 | 5.7 | 34.8 | 33 | 5.5 | 34.6 | 59 | 5.8 | 34.3 | 127 | 6.0 | 32.9 | 544 | 5.2 | 29.8 | 2,074
25 | 5.5 | 35.2 | 5.7 | 35.6 | 32 | 5.7 | 35.2 | 60 | 5.6 | 35.1 | 119 | 5.7 | 32.8 | 525 | 5.3 | 30.4 | 2,107
26 | 5.2 | 34.3 | 5.6 | 36.0 | 31 | 5.6 | 35.4 | 59 | 5.6 | 35.9 | 117 | 5.9 | 33.6 | 524 | 5.1 | 30.3 | 2,023
Mean for weeks
1–13 | 4.3 | 24.6 | 4.5 | 24.8 | 36 | 4.5 | 24.0 | 70 | 4.5 | 24.4 | 138 | 4.4 | 24.2 | 546 | 4.4 | 23.5 | 2,251
14–26 | 5.1 | 32.3 | 5.4 | 32.7 | 33 | 5.3 | 31.9 | 62 | 5.4 | 32.3 | 127 | 5.5 | 31.0 | 534 | 5.0 | 28.7 | 2,088

a Grams of feed consumed per animal per day

b Milligrams of phenolphthalein consumed per kilogram body weight per day

TABLE F2 Feed and Compound Consumption by Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

Weeks | 0 ppm | | 200 ppm | | | 375 ppm | | | 750 ppm | | | 3,000 ppm | | | 12,000 ppm
Weeks | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.0 | 17.8 | 4.0 | 17.4 | 46 | 4.2 | 17.6 | 90 | 4.1 | 17.8 | 175 | 4.3 | 18.0 | 724 | 4.2 | 17.7 | 2,840
3 | 4.4 | 18.7 | 4.2 | 17.8 | 47 | 4.0 | 18.2 | 82 | 3.8 | 17.9 | 160 | 3.9 | 18.2 | 637 | 4.3 | 18.6 | 2,782
4 | 4.0 | 19.0 | 4.2 | 18.5 | 45 | 3.9 | 18.7 | 78 | 4.0 | 18.6 | 161 | 3.9 | 18.5 | 636 | 4.2 | 19.1 | 2,644
5 | 4.1 | 19.8 | 4.0 | 19.3 | 41 | 4.2 | 19.8 | 80 | 4.0 | 19.4 | 154 | 4.1 | 19.8 | 619 | 4.5 | 19.8 | 2,731
6 | 4.1 | 20.8 | 4.3 | 20.4 | 42 | 4.3 | 19.9 | 81 | 4.5 | 20.6 | 165 | 4.5 | 20.8 | 648 | 4.6 | 20.9 | 2,646
7 | 4.4 | 21.3 | 4.2 | 20.9 | 40 | 4.7 | 21.2 | 83 | 4.3 | 21.0 | 152 | 4.6 | 21.4 | 649 | 4.7 | 21.6 | 2,622
8 | 5.2 | 21.8 | 4.9 | 21.9 | 45 | 5.2 | 21.8 | 89 | 4.8 | 22.0 | 164 | 4.6 | 22.0 | 623 | 5.0 | 22.0 | 2,714
9 | 4.7 | 22.2 | 5.2 | 22.1 | 47 | 5.7 | 22.4 | 95 | 4.5 | 22.2 | 151 | 4.6 | 21.7 | 639 | 5.2 | 22.2 | 2,800
10 | 5.1 | 22.4 | 5.3 | 21.6 | 49 | 5.3 | 22.4 | 89 | 5.2 | 22.0 | 178 | 5.0 | 22.0 | 683 | 5.1 | 22.5 | 2,700
11 | 5.2 | 22.1 | 5.5 | 22.3 | 50 | 5.7 | 23.3 | 93 | 4.8 | 22.3 | 163 | 4.8 | 22.3 | 646 | 5.4 | 23.2 | 2,779
12 | 5.1 | 22.5 | 5.6 | 22.4 | 50 | 5.9 | 23.1 | 96 | 4.8 | 22.5 | 159 | 4.9 | 22.7 | 654 | 5.3 | 23.1 | 2,750
13 | 5.1 | 22.7 | 5.9 | 23.0 | 51 | 5.4 | 23.4 | 87 | 5.2 | 23.1 | 170 | 5.0 | 22.8 | 663 | 5.5 | 23.4 | 2,829
14 | 5.5 | 23.4 | 6.1 | 23.1 | 53 | 6.1 | 23.8 | 96 | 5.2 | 23.1 | 167 | 5.2 | 23.1 | 677 | 5.4 | 23.5 | 2,741
15 | 5.1 | 22.9 | 5.9 | 23.1 | 51 | 5.5 | 23.4 | 88 | 4.8 | 23.1 | 156 | 5.3 | 22.7 | 695 | 5.6 | 23.6 | 2,830
16 | 5.3 | 23.7 | 6.1 | 23.5 | 52 | 5.4 | 24.2 | 83 | 5.1 | 23.5 | 163 | 5.7 | 23.6 | 721 | 5.7 | 23.9 | 2,861
17 | 5.4 | 23.6 | 5.7 | 23.8 | 48 | 5.4 | 23.8 | 84 | 5.4 | 24.1 | 168 | 5.4 | 24.1 | 678 | 5.6 | 24.0 | 2,778
18 | 5.8 | 24.0 | 5.8 | 23.8 | 49 | 5.5 | 24.4 | 84 | 5.3 | 24.2 | 164 | 5.9 | 24.0 | 737 | 5.5 | 24.1 | 2,755
19 | 5.9 | 24.5 | 6.1 | 24.4 | 50 | 6.0 | 24.7 | 91 | 6.1 | 24.6 | 185 | 5.9 | 24.4 | 726 | 5.8 | 24.5 | 2,862
20 | 5.4 | 24.5 | 6.5 | 25.0 | 52 | 5.6 | 25.1 | 84 | 5.8 | 24.8 | 174 | 6.0 | 24.7 | 727 | 6.1 | 25.0 | 2,927
21 | 5.4 | 24.7 | 5.9 | 24.8 | 48 | 5.0 | 25.0 | 75 | 5.4 | 24.5 | 167 | 5.5 | 24.3 | 682 | 5.3 | 24.7 | 2,568
22 | 5.7 | 24.4 | 6.1 | 25.6 | 48 | 5.2 | 24.6 | 80 | 5.6 | 25.4 | 165 | 6.0 | 25.2 | 709 | 5.5 | 24.9 | 2,664
23 | 5.8 | 24.2 | 5.7 | 24.8 | 46 | 6.0 | 25.6 | 88 | 5.4 | 24.3 | 167 | 5.6 | 24.6 | 687 | 6.2 | 25.6 | 2,908
24 | 5.7 | 24.8 | 6.0 | 25.0 | 48 | 5.6 | 25.4 | 83 | 5.9 | 25.5 | 173 | 6.1 | 25.2 | 726 | 6.1 | 25.5 | 2,873
25 | 6.2 | 25.6 | 6.3 | 25.6 | 50 | 6.3 | 26.4 | 89 | 5.8 | 25.1 | 172 | 6.2 | 25.3 | 731 | 5.9 | 25.4 | 2,798
26 | 6.3 | 25.3 | 6.1 | 25.5 | 48 | 6.1 | 26.5 | 86 | 5.6 | 25.1 | 166 | 6.0 | 25.1 | 719 | 6.0 | 25.4 | 2,850
Mean for weeks
1–13 | 4.6 | 20.9 | 4.8 | 20.6 | 46 | 4.9 | 21.0 | 87 | 4.5 | 20.8 | 163 | 4.5 | 20.8 | 652 | 4.8 | 21.2 | 2,736
14–26 | 5.6 | 24.3 | 6.0 | 24.5 | 49 | 5.7 | 24.8 | 85 | 5.5 | 24.4 | 168 | 5.7 | 24.3 | 709 | 5.7 | 24.6 | 2,801

a Grams of feed consumed per animal per day

b Milligrams of phenolphthalein consumed per kilogram body weight per day