# APPENDIX E CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization of Phenolphthalein

Phenolphthalein was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (13427LF). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC), Galbraith Laboratories, Inc. (Knoxville, TN), and the study laboratory, Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the phenolphthalein study are on file at the National Institute of Environmental Health Sciences.

Lot 13427LF, a light brown/yellowish-white powder, was identified as phenolphthalein by the analytical chemistry laboratory using direct probe mass spectrometry and infrared (IR), ultraviolet/visible, and proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using IR spectroscopy; the spectra were consistent with the structure of phenolphthalein, showed absorption maxima consistent with literature values, matched spectra of a frozen reference standard from the same lot, or matched literature spectra (EPA/NIH, 1978; Aldrich, 1981, 1985; Merck, 1989). Representative IR and proton NMR spectra are presented in Figures E1 and E2. The melting point range (264° to 265° C) was consistent with a literature value (Merck, 1989).

The moisture content of lot 13427LF was determined by Galbraith Laboratories, Inc., using Karl Fischer titration; this laboratory also performed elemental analyses of lot 13427LF. The purity of lot 13427LF was determined by the analytical chemistry laboratory using high-performance liquid chromatography (HPLC) by system A (Table E1) and by the study laboratory using HPLC by system B.

For lot 13427LF, Karl Fischer titration indicated 0.507% water. Elemental analyses for carbon, hydrogen, and oxygen were consistent with the theoretical values for phenolphthalein. HPLC analyses by system A indicated one major peak and one impurity of 0.4%. The overall purity of lot 13427LF was determined to be greater than 99%.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using HPLC by system B. These studies indicated that phenolphthalein was stable as a bulk chemical for at least 14 days when stored protected from light at temperatures up to 60° C. To ensure stability, the bulk chemical was stored in the original shipping containers at room temperature, protected from light. Stability was monitored during the study using HPLC by system B; no degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately every 4 weeks by mixing phenolphthalein with feed (Table E2). A premix was prepared by hand and then blended with additional feed in a Patterson-Kelley twin-shell blender for 15 minutes using an intensifier bar for the initial 5 minutes. Formulations were stored in plastic buckets at less than or equal to −20° C for up to 42 days, with the exception of formulations prepared on November 29, 1999, which were originally stored at room temperature for 2 days and then transferred to −20° C storage.

Homogeneity studies of the 200 and 12,000 ppm dose formulations were performed by the analytical chemistry and study laboratories using HPLC by system C (Table E1). Stability studies of the 200 ppm dose formulation were performed by the analytical chemistry laboratory using HPLC by system C. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed glass bottles protected from light at −20° C and for at least 7 days under simulated animal room conditions (exposed to light and air) in the absence of animal excreta.

Periodic analyses of the dose formulations of phenolphthalein were conducted by the study laboratory using HPLC by system B. All 15 dose formulations analyzed and used in the study were within 10% of the target concentrations; the dose formulations prepared on November 29, 1999, were not adversely affected by storage at room temperature for 2 days (Table E3). Animal room samples of these dose formulations were also analyzed; two of five animal room samples were within 10% of the target concentrations. Degradation was attributed to unavoidable excreta in the feeders.

FIGURE E1 Infrared Absorption Spectrum of Phenolphthalein

FIGURE E2 Proton Nuclear Magnetic Resonance Spectrum of Phenolphthalein

TABLE E1 High-Performance Liquid Chromatography Systems Used in the 27-Week Feed Study of Phenolphthalein^a^

Detection System | Column | Solvent System
System A
Ultraviolet (254 nm) light | Primesphere™ C_18_-HC, 150 mm × 3.2 mm, 5 μm (Phenomenex, Torrance, CA) | A) Acetonitrile and B) 0.00016 M monobasic potassium phosphate, pH 4.5, adjusted with phosphoric acid; linear gradient from 10% A:90% B to 90% A:10% B in 15 minutes at a flow rate of 0.5 mL/minute, held for 10 minutes
System B
Ultraviolet (254 nm) light | Primesphere™ C_18_-HC, 150 mm × 3.2 mm, 5 μm or Inertsil™ ODS-2, 150 mm × 3.0 mm, 5 μm (Phenomenex) | Acetonitrile:0.02 M monobasic potassium phosphate (40:60); pH 4.5, adjusted with phosphoric acid; flow rate 0.5 mL/minute; propiophenone as internal standard
System C
Ultraviolet (254 nm) light | Symmetry^®^ C_18_ 150 mm × 3.9 mm, 5 μm (Waters Corporation, Milford, MA) | Acetonitrile:0.02 M monobasic potassium phosphate (45:55); pH 4.5, adjusted with phosphoric acid; flow rate 0.5 mL/minute; propiophenone as internal standard

a The high-performance liquid chromatographs were manufactured by Waters Corporation (Milford, MA).

TABLE E2 Preparation and Storage of Dose Formulations in the 27-Week Feed Study of Phenolphthalein

Preparation
A premix of feed and phenolphthalein was prepared in a stainless steel beaker, then layered into the remaining feed and blended in a Patterson-Kelley twin-shell blender for 15 minutes with the intensifier bar on for the first 5 minutes. The dose formulations were prepared approximately every 4 weeks.
Chemical Lot Number
13427LF
Maximum Storage Time
42 days
Storage Conditions
Dose formulations were stored in amber glass bottles sealed with Teflon^®^-lined lids at −20° C with the exception of formulations prepared on November 29, 1999, which were originally stored at room temperature for 2 days and then transferred to −20° C storage.
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

TABLE E3 Results of Analyses of Dose Formulations Administered to Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
November 29, 1999 | November 30, 1999 | 200 | 188.6 | −6
| | 375 | 368.9 | −2
| | 750 | 743.8 | −1
| | 3,000 | 3,012 | 0
| | 12,000 | 11,900 | −1
| December 3, 1999^b^ | 200 | 191.4 | −4
| | 375 | 367.1 | −2
| | 750 | 727.3 | −3
| | 3,000 | 3,053 | +2
| | 12,000 | 11,700 | −3
| January 7–8, 2000^c^ | 200 | 115.2 | −42
| | 375 | 226.0 | −40
| | 750 | 601.7 | −20
| | 3,000 | 3,199 | +7
| | 12,000 | 11,040 | −8
February 21, 2000 | February 22, 2000 | 200 | 186.8 | −7
| | 375 | 349.3 | −7
| | 750 | 706.8 | −6
| | 3,000 | 2,941 | −2
| | 12,000 | 12,240 | +2
May 15, 2000 | May 16, 2000 | 200 | 183.1 | −8
| | 375 | 347.4 | −7
| | 750 | 720.1 | −4
| | 3,000 | 2,959 | −1
| | 12,000 | 12,240 | +2

a Results of duplicate analyses

b Results of reanalysis of dose formulations originally stored at room temperature for 2 days before being transferred to −20° C storage

c Animal room samples