# APPENDIX D REPRODUCTIVE TISSUE EVALUATIONS

TABLE D1 Summary of Reproductive Tissue Evaluations for Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein^a^

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
n | 13 | 15 | 15 | 13 | 15 | 14
Weights (g)
Necropsy body weight | 35.7 ± 0.8 | 36.4 ± 1.1 | 36.1 ± 0.9 | 36.6 ± 0.7 | 34.8 ± 0.8 | 31.3 ± 0.5^**^
L. Cauda epididymis | 0.0145 ± 0.0007 | 0.0153 ± 0.0008 | 0.0153 ± 0.0009 | 0.0160 ± 0.0008 | 0.0128 ± 0.0005 | 0.0112 ± 0.0004^**^
L. Epididymis | 0.0491 ± 0.0016 | 0.0494 ± 0.0014 | 0.0482 ± 0.0023 | 0.0498 ± 0.0019 | 0.0396 ± 0.0018^**^ | 0.0320 ± 0.0016^**^
L. Testis | 0.1222 ± 0.0035 | 0.1202 ± 0.0019 | 0.1125 ± 0.0070 | 0.1181 ± 0.0029 | 0.0604 ± 0.0032^**^ | 0.0408 ± 0.0022^**^
Spermatid measurements
Spermatid heads (10^6^/testis) | 18.90 ± 1.02^b^ | 18.39 ± 0.80^c^ | 18.65 ± 1.50^c^ | 18.93 ± 0.52^b^ | 6.34 ± 0.88^**^,^c^ | 2.63 ± 0.44^**^,^d^
Epididymal spermatozoal measurements
Sperm heads (10^6^/g cauda epididymis) | 814 ± 31 | 910 ± 95 | 780 ± 74 | 813 ± 56 | 275 ± 16^**^ | 100 ± 24^**^
Sperm heads (10^6^/cauda) | 11.62 ± 0.38 | 13.22 ± 0.69 | 11.96 ± 1.17 | 12.87 ± 0.97 | 3.57 ± 0.27^**^ | 1.07 ± 0.25^**^
Sperm motility (%) | 82.71 ± 1.31 | 82.90 ± 1.00 | 78.36 ± 5.68 | 79.05 ± 1.35 | 81.79 ± 1.17 | 35.97 ± 10.88^**^

** Significantly different (P≤0.01) from the control group by Williams’ test (body weights and tissue weights) or Shirley’s test (spermatid and epididymal spermatozoal measurements)

a Data are presented as mean ± standar

b n=12

c n=14

d n=13