# APPENDIX C ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE C1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein^a^

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Male
n | 13 | 15 | 15 | 13 | 15 | 14
Necropsy body wt | 35.7 ± 0.8 | 36.4 ± 1.1 | 36.1 ± 0.9 | 36.6 ± 0.7 | 34.8 ± 0.8 | 31.3 ± 0.5^**^
Heart
Absolute | 0.226 ± 0.010 | 0.230 ± 0.009 | 0.210 ± 0.008 | 0.247 ± 0.010 | 0.213 ± 0.009 | 0.201 ± 0.008
Relative | 6.340 ± 0.261 | 6.393 ± 0.305 | 5.821 ± 0.191 | 6.743 ± 0.232 | 6.125 ± 0.243 | 6.439 ± 0.285
R. Kidney
Absolute | 0.278 ± 0.004 | 0.293 ± 0.009 | 0.289 ± 0.010 | 0.284 ± 0.006 | 0.268 ± 0.006 | 0.251 ± 0.005^*^
Relative | 7.820 ± 0.143 | 8.074 ± 0.149 | 7.983 ± 0.168 | 7.758 ± 0.085 | 7.730 ± 0.182 | 8.029 ± 0.146
Liver
Absolute | 1.734 ± 0.057 | 1.827 ± 0.082 | 1.751 ± 0.070^b^ | 1.851 ± 0.057 | 1.769 ± 0.058 | 1.700 ± 0.052
Relative | 48.573 ± 1.123 | 50.083 ± 1.364 | 48.312 ± 1.128^b^ | 50.458 ± 0.812 | 50.905 ± 1.292 | 54.316 ± 1.257^**^
Lung
Absolute | 0.247 ± 0.011 | 0.239 ± 0.005 | 0.228 ± 0.006 | 0.283 ± 0.010^*^ | 0.262 ± 0.011 | 0.238 ± 0.012
Relative | 6.922 ± 0.258 | 6.651 ± 0.253 | 6.335 ± 0.193 | 7.748 ± 0.257 | 7.568 ± 0.354 | 7.650 ± 0.410
R. Testis
Absolute | 0.128 ± 0.003 | 0.125 ± 0.002 | 0.126 ± 0.002^b^ | 0.124 ± 0.004 | 0.063 ± 0.003^**^ | 0.046 ± 0.003^**^
Relative | 3.592 ± 0.114 | 3.485 ± 0.113 | 3.436 ± 0.051^b^ | 3.382 ± 0.085 | 1.815 ± 0.087^**^ | 1.473 ± 0.090^**^
Thymus
Absolute | 0.039 ± 0.002 | 0.035 ± 0.002 | 0.039 ± 0.003 | 0.039 ± 0.002 | 0.036 ± 0.002 | 0.031 ± 0.002
Relative | 1.104 ± 0.064 | 0.961 ± 0.067 | 1.077 ± 0.060 | 1.065 ± 0.043 | 1.052 ± 0.071 | 0.988 ± 0.062
Female
n | 15 | 13 | 14 | 15 | 14 | 15
Necropsy body wt | 25.7 ± 0.4 | 25.7 ± 0.4 | 27.2 ± 0.8 | 25.9 ± 0.4 | 26.0 ± 0.3 | 26.0 ± 0.3
Heart
Absolute | 0.154 ± 0.003 | 0.153 ± 0.006 | 0.155 ± 0.003 | 0.162 ± 0.006 | 0.169 ± 0.008 | 0.152 ± 0.004
Relative | 6.001 ± 0.150 | 5.973 ± 0.199 | 5.749 ± 0.156 | 6.259 ± 0.274 | 6.536 ± 0.349 | 5.855 ± 0.127
R. Kidney
Absolute | 0.201 ± 0.002 | 0.192 ± 0.006 | 0.199 ± 0.006 | 0.201 ± 0.004 | 0.207 ± 0.005 | 0.208 ± 0.005^b^
Relative | 7.841 ± 0.162 | 7.481 ± 0.167 | 7.368 ± 0.213 | 7.739 ± 0.094 | 7.990 ± 0.193 | 8.041 ± 0.174^b^
Liver
Absolute | 1.268 ± 0.028 | 1.230 ± 0.037 | 1.331 ± 0.044 | 1.272 ± 0.043 | 1.311 ± 0.027 | 1.324 ± 0.026
Relative | 49.294 ± 0.918 | 47.848 ± 0.927 | 49.004 ± 0.871 | 48.946 ± 1.179 | 50.525 ± 1.089 | 50.961 ± 0.995
Lung
Absolute | 0.240 ± 0.010 | 0.245 ± 0.010 | 0.251 ± 0.012 | 0.259 ± 0.013 | 0.237 ± 0.009 | 0.223 ± 0.008
Relative | 9.347 ± 0.413 | 9.532 ± 0.328 | 9.284 ± 0.450 | 9.957 ± 0.456 | 9.124 ± 0.349 | 8.598 ± 0.337
Thymus
Absolute | 0.040 ± 0.003 | 0.041 ± 0.002 | 0.039 ± 0.001 | 0.039 ± 0.003 | 0.038 ± 0.002^c^ | 0.033 ± 0.002
Relative | 1.536 ± 0.116 | 1.593 ± 0.093 | 1.442 ± 0.060 | 1.481 ± 0.078 | 1.446 ± 0.081^c^ | 1.259 ± 0.085

* Significantly different (P≤0.05) from the control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=14

c n=13