# APPENDIX B GENETIC TOXICOLOGY

TABLE B1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Haploinsufficient p16^Ink4a^/p19^Arf^ Mice Following Administration of Phenolphthalein in Feed for up to 27 Weeks^a^

Compound | Dose (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
6.5 Weeks
Feed^d^ | | 14 | 0.89 ± 0.09 | | 1.757 ± 0.09
Phenolphthalein | 200 | 15 | 0.97 ± 0.15 | 0.3854 | 1.813 ± 0.13
| 375 | 15 | 1.20 ± 0.14 | 0.1271 | 1.700 ± 0.11
| 750 | 13 | 1.19 ± 0.17 | 0.1400 | 1.785 ± 0.11
| 3,000 | 15 | 1.83 ± 0.18 | 0.0011 | 2.240 ± 0.12
| 12,000 | 14 | 3.32 ± 0.28 | 0.0000 | 2.121 ± 0.14
| | | P=0.000^e^
13 Weeks
Feed | | 13 | 2.23 ± 0.26 | | 3.346 ± 0.34
Phenolphthalein | 200 | 15 | 1.33 ± 0.23 | 0.9944 | 3.200 ± 0.36
| 375 | 15 | 1.83 ± 0.25 | 0.8520 | 3.527 ± 0.34
| 750 | 13 | 1.96 ± 0.30 | 0.7489 | 4.338 ± 0.49
| 3,000 | 15 | 2.20 ± 0.35 | 0.5308 | 3.113 ± 0.30
| 12,000 | 14 | 4.68 ± 0.44 | 0.0000 | 2.521 ± 0.23
| | | P=0.000
19.5 Weeks
Feed | | 13 | 1.88 ± 0.24 | | 2.392 ± 0.16
Phenolphthalein | 200 | 15 | 1.77 ± 0.39 | 0.5966 | 2.247 ± 0.16
| 375 | 15 | 2.03 ± 0.24 | 0.3832 | 2.233 ± 0.19
| 750 | 13 | 1.73 ± 0.42 | 0.6215 | 2.177 ± 0.21
| 3,000 | 15 | 2.17 ± 0.40 | 0.2900 | 2.527 ± 0.13
| 12,000 | 14 | 4.46 ± 0.49 | 0.0000 | 2.743 ± 0.19
| | | P=0.000
27 Weeks
Feed | | 13 | 1.35 ± 0.15 | | 2.469 ± 0.16
Phenolphthalein | 200 | 15 | 1.73 ± 0.31 | 0.1788 | 2.440 ± 0.22
| 375 | 15 | 1.30 ± 0.27 | 0.5473 | 3.540 ± 1.12
| 750 | 13 | 1.19 ± 0.23 | 0.6520 | 2.154 ± 0.21
| 3,000 | 15 | 2.37 ± 0.43 | 0.0140 | 1.920 ± 0.08
| 12,000 | 14 | 4.68 ± 0.57 | 0.0000 | 2.921 ± 0.29
| | | P=0.000
Female
6.5 Weeks
Feed | | 15 | 0.60 ± 0.16 | | 2.307 ± 0.16
Phenolphthalein | 200 | 13 | 0.81 ± 0.17 | 0.1764 | 1.977 ± 0.12
| 375 | 14 | 0.89 ± 0.18 | 0.0977 | 1.714 ± 0.10
| 750 | 15 | 0.93 ± 0.16 | 0.0701 | 1.940 ± 0.11
| 3,000 | 14 | 1.61 ± 0.20 | 0.0001 | 2.107 ± 0.14
| 12,000 | 15 | 2.57 ± 0.20 | 0.0000 | 2.213 ± 0.12
| | | P=0.000
13 Weeks
Feed | | 15 | 0.87 ± 0.26 | | 2.013 ± 0.23
Phenolphthalein | 200 | 13 | 1.31 ± 0.22 | 0.1018 | 1.877 ± 0.13
| 375 | 14 | 1.39 ± 0.21 | 0.0652 | 2.250 ± 0.19
| 750 | 15 | 0.97 ± 0.18 | 0.3732 | 1.693 ± 0.08
| 3,000 | 14 | 1.29 ± 0.33 | 0.1088 | 1.907 ± 0.17
| 12,000 | 15 | 3.13 ± 0.45 | 0.0000 | 2.180 ± 0.17
| | | P=0.000
19.5 Weeks
Feed | | 15 | 1.07 ± 0.25 | | 2.153 ± 0.18
Phenolphthalein | 200 | 13 | 0.96 ± 0.22 | 0.6216 | 2.315 ± 0.25
| 375 | 14 | 0.57 ± 0.19 | 0.9504 | 2.307 ± 0.21
| 750 | 15 | 0.80 ± 0.23 | 0.8026 | 1.787 ± 0.08
| 3,000 | 14 | 1.18 ± 0.24 | 0.3744 | 2.257 ± 0.20
| 12,000 | 15 | 3.40 ± 0.38 | 0.0000 | 2.073 ± 0.14
| | | P=0.000
27 Weeks
Feed | | 15 | 1.07 ± 0.22 | | 2.333 ± 0.12
Phenolphthalein | 200 | 13 | 0.50 ± 0.17 | 0.9909 | 2.523 ± 0.18
| 375 | 14 | 0.36 ± 0.11 | 0.9992 | 2.700 ± 0.20
| 750 | 15 | 1.30 ± 0.25 | 0.2029 | 2.553 ± 0.27
| 3,000 | 14 | 1.32 ± 0.20 | 0.1869 | 4.057 ± 1.48
| 12,000 | 15 | 2.83 ± 0.33 | 0.0000 | 2.793 ± 0.29
| | | P=0.000

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the controls, significant at P≤0.005 (ILS, 1990)

d Control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)