# APPENDIX A SUMMARY OF LESIONS IN HAPLOINSUFFICIENT p16^Ink4a^/p19^Arf^ MICE IN THE 27-WEEK FEED STUDY OF PHENOLPHTHALEIN

TABLE A1 Summary of the Incidence of Neoplasms in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein^a^

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 1
Natural deaths | 1 | | | 2 | | 1
Survivors
Terminal sacrifice | 13 | 15 | 15 | 13 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine large, colon | (14) | (15) | (15) | (14) | (15) | (14)
Intestine large, rectum | (14) | (15) | (15) | (14) | (15) | (14)
Intestine large, cecum | (14) | (15) | (15) | (14) | (15) | (14)
Intestine small, duodenum | (14) | (15) | (15) | (14) | (15) | (14)
Intestine small, jejunum | (14) | (15) | (15) | (14) | (15) | (14)
Intestine small, ileum | (14) | (15) | (15) | (14) | (15) | (14)
Liver | (15) | (15) | (15) | (14) | (15) | (14)
Histiocytic sarcoma | | | 1 (7%)
Stomach, forestomach | (14) | (15) | (15) | (15) | (15) | (14)
Stomach, glandular | (14) | (15) | (15) | (14) | (15) | (14)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Endocrine System
Adrenal cortex | (14) | (15) | (15) | (14) | (15) | (14)
General Body System
None
Genital System
Epididymis | (15) | (15 | (15) | (15) | (15) | (15)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 1 (7%) | 1 (7%)
Lymph node | (11) | (11) | (9) | (10) | (15) | (12)
Mediastinal, histiocytic sarcoma | | | 1 (11%)
Lymph node, mandibular | (14) | (15) | (15) | (14) | (15) | (13)
Lymph node, mesenteric | (14) | (15) | (15) | (14) | (15) | (14)
Spleen | (14) | (15) | (15) | (14) | (15) | (14)
Thymus | (14) | (15) | (15) | (14) | (15) | (14)
Integumentary System
Skin | (15) | (15) | (15) | (14) | (15) | (15)
Musculoskeletal System
None
Nervous System
Brain | (15) | (15) | (15) | (14) | (15) | (14)
Respiratory System
Lung | (15) | (15) | (15) | (14) | (15) | (15)
Histiocytic sarcoma | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (14) | (15) | (15) | (14) | (15) | (15)
Urinary bladder | (14) | (15) | (15) | (14) | (15) | (14)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | 1 (7%) | 1 (7%)
Lymphoma malignant | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | | 1 | 1
Total primary neoplasms | 1 | | 1 | 1
Total animals with malignant neoplasms | 1 | | 1 | 1
Total malignant neoplasms | 1 | | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein^a^

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 1
Natural deaths | 1 | | | 2 | | 1
Survivors
Terminal sacrifice | 13 | 15 | 15 | 13 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (14) | (15) | (14)
Hematopoietic cell proliferation | | | 1 (7%)
Inflammation, chronic | 11 (73%) | 8 (53%) | 7 (47%) | 9 (64%) | 10 (67%) | 5 (36%)
Mesentery | | (1)
Fat, necrosis | | 1 (100%)
Stomach, glandular | (14) | (15) | (15) | (14) | (15) | (14)
Epithelium, cyst | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (14) | (15) | (15) | (14) | (15) | (14)
Hyperplasia, focal | | | | 4 (29%) | 1 (7%)
Hypertrophy, focal | 4 (29%) | 3 (20%) | 1 (7%) | 1 (7%) | 2 (13%)
Thyroid gland | (14) | (15) | (15) | (14) | (15) | (15)
Infiltration cellular, polymorphonuclear | | | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | (15 | (15) | (15) | (15) | (15)
Hypospermia | | | 1 (7%) | | 15 (100%) | 14 (93%)
Inflammation, chronic | | | | 1 (7%)
Inflammation, granulomatous | | | 1 (7%)
Mineralization | | 1 (7%)
Testes | (15) | (15) | (15) | (15) | (15) | (15)
Germinal epithelium, atrophy | | 1 (7%) | 1 (7%) | | 15 (100%) | 14 (93%)
Interstitial cell, hyperplasis | | 1 (7%) | 1 (7%) | | 15 (100%) | 14 (93%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15) | (15)
Hyperplasia | | 1 (7%)
Lymph node, mandibular | (14) | (15) | (15) | (14) | (15) | (13)
Hyperplasia, lymphoid | 2 (14%) | 1 (7%) | 2 (13%) | | 3 (20%) | 1 (8%)
Lymph node, mesenteric | (14) | (15) | (15) | (14) | (15) | (14)
Atrophy | | 1 (7%) | 1 (7%) | 1 (7%)
Hyperplasia, lymphoid | | | 1 (7%) | | 2 (13%) | 1 (7%)
Spleen | (14) | (15) | (15) | (14) | (15) | (14)
Hematopoietic cell proliferation | 2 (14%) | 5 (33%) | 3 (20%) | 1 (7%) | 2 (13%) | 14 (100%)
Infiltration cellular, mononuclear cell | 1 (7%)
Pigmentation | | | | | | 1 (7%)
Capsule, fibrosis | | | | | | 1 (7%)
Lymphoid follicle, atrophy | | | | 1 (7%)
Thymus | (14) | (15) | (15) | (14) | (15) | (14)
Atrophy, diffuse | | | | 1 (7%)
Hyperplasia, atypical | | | 1 (7%) | | 1 (7%)
Hyperplasia, lymphoid | | | 1 (7%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (14) | (15) | (15)
Inflammation, chronic | | 2 (13%) | | 2 (14%) | 1 (7%)
Alveolar epithelium, hyperplasia | | | | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (14) | (15) | (15) | (14) | (15) | (15)
Nephropathy | 6 (43%) | 7 (47%) | 8 (53%) | 6 (43%) | 15 (100%) | 14 (93%)
Renal tubule, accumulation, hyaline droplet | | | 1 (7%)
Renal tubule, hypertrophy | | | | 10 (71%) | 15 (100%) | 14 (93%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein^a^

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1
Natural deaths | | 2 | | | 1
Survivors
Terminal sacrifice | 15 | 13 | 14 | 15 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Pancreas | | (1)
Histiocytic sarcoma | | 1 (100%)
Stomach, glandular | (15) | (14) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal medulla | (15) | (14) | (15) | (15) | (15) | (15)
Pheochromocytoma, benign | | | | | 1 (7%)
General Body System
None
Genital System
Ovary | (15) | (14) | (15) | (15) | (14) | (15)
Histiocytic sarcoma | | 1 (7%) | 2 (13%)
Periovarian tissue, hystiocytic sarcoma | | | | | | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Sarcoma | | | | | 1 (7%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 1 (7%) | 1 (7%)
Lymph node | (13) | (10) | (13) | (14) | (13) | (13)
Deep cervical, histiocytic sarcoma | | 1 (10%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Spleen | (15) | (14) | (14) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Thymus | (15) | (15) | (15) | (15) | (14) | (15)
Histiocytic sarcoma | | 1 (7%)
Integumentary System
None
Musculoskeletal System
Bone | | (1) | | | | (1)
Histiocytic sarcoma | | 1 (100%)
Skeletal muscle | | | | | (1)
Histiocytic sarcoma | | | | | 1 (100%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%) | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | | 1 | 2 | 1 | 2 | 1
Total primary neoplasms | | 1 | 2 | 1 | 4 | 1
Total animals with benign neoplasms | | | | | 1
Total malignant neoplasms | | | | | 1
Total animals with malignant neoplasms | | 1 | 2 | 1 | 1 | 1
Total malignant neoplasms | | 1 | 2 | 1 | 3 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Feed Study of Phenolphthalein^a^

| 0 ppm | 200 ppm | 375 ppm | 750 ppm | 3,000 ppm | 12,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1
Natural deaths | | 2 | | | 1
Survivors
Terminal sacrifice | 15 | 13 | 14 | 15 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine small, jejunum | (15) | (14) | (15) | (15) | (15) | (15)
Infiltration cellular, polymorphonuclear | | | 1 (7%)
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Basophilic focus | | | | | | 1 (7%)
Inflammation, chronic | 10 (67%) | 8 (53%) | 12 (80%) | 10 (67%) | 7 (47%) | 8 (53%)
Necrosis, focal | 1 (7%) | | | | | 1 (7%)
Stomach, forestomach | (15) | (14) | (15) | (15) | (15) | (15)
Ulcer | | | | | 1 (100%)
Stomach, glandular | (15) | (14) | (15) | (15) | (15) | (15)
Hemorrhage | | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Thyroid gland | (15) | (14) | (15) | (15) | (15) | (15)
Inflammation, granulomatous | 1 (7%)
General Body System
None
Genital System
Ovary | (15) | (14) | (15) | (15) | (14) | (15)
Cyst | 1 (7%) | 1 (7%) | | | 1 (7%) | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 15 (100%) | 12 (80%) | 14 (93%) | 15 (100%) | 13 (87%) | 14 (93%)
Vagina | | | | | | (1)
Epithelium, hyperplasia | | | | | | 1 (100%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | | 2 (13%) | | | 2 (13%)
Hematopoietic cell proliferation | | 1 (7%)
Hemorrhage | | 1 (7%)
Hyperplasia, lymphoid | 4 (27%) | 2 (13%) | 2 (13%) | | 1 (7%) | 6 (40%)
Lymph node, mesenteric | (15) | (14) | (15) | (15) | (15) | (15)
Atrophy | 1 (7%) | 1 (7%) | 1 (7%) | | 2 (13%) | 2 (13%)
Hematopoietic cell proliferation | | | 1 (7%)
Hyperplasia, lymphoid | | | 1 (7%)
Infiltration cellular, polymorphonuclear | | 1 (7%)
Spleen | (15) | (14) | (14) | (15) | (15) | (15)
Hematopoietic cell proliferation | 2 (13%) | 5 (36%) | 9 (64%) | 8 (53%) | 7 (47%) | 13 (87%)
Lymphoid follicle, atrophy | | 1 (7%) | | | 2 (13%)
Lymphoid follicle, hyperplasia | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15) | (14) | (15)
Atrophy, diffuse | | 1 (7%) | 1 (7%) | | 1 (7%)
Hyperplasia, atypical | | | 1 (7%) | | 3 (21%) | 5 (33%)
Hyperplasia, lymphoid | 1 (7%)
Integumentary System
None
Musculoskeletal System
Bone | | (1) | | | | (1)
Hyperplasia | | 1 (100%)
Nervous System
Brain | (15) | (15) | (15) | (15) | (15) | (15)
Hemorrhage | | 1 (7%)
Neuron, necrosis | | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | 2 (13%) | 1 (7%) | 1 (7%) | 3 (20%) | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Hydronephrosis | | | | | 1 (7%) | 1 (7%)
Nephropathy | 10 (67%) | 6 (40%) | 8 (53%) | 8 (53%) | 7 (47%) | 11 (73%)
Renal tubule, mineralization | 1 (7%)
Ureter | | | | | | (1)
Cyst | | | | | | 1 (100%)

a Number of animals examined microscopically at the site and the number of animals with lesion