# REFERENCES

The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Spectrum 1:508B. Aldrich Chemical Company, Inc., Milwaukee, WI.
The Aldrich Library of ^13^C and ^1^H FT-NMR Spectra (1992). 1st ed. (C.J. Pouchert and J. Behnke, Eds.), p. 792, Spectrum A. Aldrich Chemical Company, Inc., Milwaukee, WI.
Anna, C.H., Maronpot, R.R., Pereira, M.A., Foley, J.F., Malarkey, D.E., and Anderson, M.W. (1994). Ras proto-oncogene activation in dichloroacetic acid-, trichloroethylene- and tetrachloroethylene-induced liver tumors in B6C3F_1_ mice. Carcinogenesis 15, 2255–2261.7955063
Battalora, M.S., Spalding, J.W., Szczesniak, C.J., Cape, J.E., Morris, R.J., Trempus, C.S., Bortner, C.D., Lee, B.M., and Tennant, R.W. (2001). Age-dependent skin tumorigenesis and transgene expression in the Tg.AC (v-Ha-ras) transgenic mouse. Carcinogenesis 22, 651–659.11285202
Bhat, H.K., Kanz, M.F., Campbell, G.A., and Ansari, G.A. (1991). Ninety day toxicity study of chloroacetic acids in rats. Fundam. Appl. Toxicol. 17, 240–253.1765218
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Boorman, G.A., Dellarco, V., Dunnick, J.K., Chapin, R.E., Hunter, S., Hauchman, F., Gardner, H., Cox, M., and Sills, R.C., (1999). Drinking water disinfection byproducts: Review and approach to toxicity evaluation. Environ. Health Perspect. 107, 207–217.10229719
Bull, R.J., Sanchez, I.M., Nelson, M.A., Larson, J.L., and Lansing, A.J. (1990). Liver tumor induction in B6C3F_1_ mice by dichloroacetate and trichloroacetate. Toxicology 63, 341–359.2219130
Bull, R.J., Birnbaum, L.S., Cantor, K.P., Rose, J.B., Butterworth, B.E., Pegram, R., and Tuomisto, J. (1995). Water chlorination: Essential process or cancer hazard? Fundam. Appl. Toxicol. 28, 155–166.8835225
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Cantor, K.P., Lynch, C.F., Hildesheim, M.E., Dosemeci, M., Lubin, J., Alavanja, M., and Craun, G. (1998). Drinking water source and chlorination byproducts. I. Risk of bladder cancer. Epidemiology 9, 21–28.9430264
Chang, L.W., Daniel, F.B., and DeAngelo, A.B. (1992). Analysis of DNA strand breaks induced in rodent liver in vivo, hepatocytes in primary culture, and a human cell line by chlorinated acetic acids and chlorinated acetaldehydes. Environ. Mol. Mutagen. 20, 277–288.1330547
Chevrier, C., Junod, B., and Cordier, S. (2004). Does ozonation of drinking water reduce the risk of bladder cancer? Epidemiology 15, 605–614.15308961
Cicmanec, J.L., Condie, L.W., Olson, G.R., and Wang, S.R. (1991). 90-Day toxicity study of dichloroacetate in dogs. Fundam. Appl. Toxicol. 17, 376–389.1765225
Code of Federal Regulations (CFR) 21, Part 58.
Code of Federal Regulations (CFR) 40, Part 141.
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Daniel, F.B., DeAngelo, A.B., Stober, J.A., Olson, G.R., and Page, N.P. (1992). Hepatocarcinogenicity of chloral hydrate, 2-chloroacetaldehyde, and dichloroacetic acid in the male B6C3F_1_ mouse. Fundam. Appl. Toxicol. 19, 159–168.1516771
Dass, S.B., Bucci, T.J., Heflich, R.H., and Casciano, D.A. (1999). Evaluation of the transgenic p53 (+/−) mouse for detecting genotoxic liver carcinogens in a short-term bioassay. Cancer Lett. 143, 81–85.10465341
DeAngelo, A.B., Daniel, F.B., Most, B.M., and Olson, G.R. (1996). The carcinogenicity of dichloroacetic acid in the male Fischer 344 rat. Toxicology 114, 207–221.8980710
DeAngelo, A.B., George, M.H., and House, D.E. (1999). Hepatocarcinogenicity in the male B6C3F1 mouse following a lifetime exposure to dichloroacetic acid in the drinking water: Dose-response determination and modes of action. J. Toxicol. Environ. Health A. 58, 485–507.10632141
DeMarini, D.M., Perry, E., and Shelton, M.L. (1994). Dichloroacetic acid and related compounds: Induction of prophage in E. coli and mutagenicity and mutation spectra in Salmonella TA100. Mutagenesis 9, 429–437.7837977
Dixon, W.J., and Massey, F.J., Jr. (1957). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunson, D.B., Haseman, J.K., van Birgelen, A.P.J.M., Stasiewicz, S., and Tennant, R.W. (2000). Statistical analysis of skin tumor data from Tg.AC mouse bioassays. Toxicol. Sci. 55, 293–302.10828260
Eastin, W.C., Haseman, J.K., Mahler, J.F., and Bucher, J.R. (1998). The National Toxicology Program evaluation of genetically altered mice as predictive models for identifying carcinogens. Toxicol. Pathol. 26, 461–473.9715504
Fawell, J., Robinson, D., Bull, R., Birnbaum, L., Boorman, G., Butterworth, B., Daniel, P., Galal-Gorchev, H., Hauchman, F., Julkunen, P., Klaassen, C., Krasner, S., Orme-Zavaleta, J., Reif, J., and Tardiff, R. (1997). Disinfection by-products in drinking water: Critical issues in health effects research. Environ. Health Perspect. 105, 108–109.9074890
Finnberg, N., Stenius, U., and Hogberg, J. (2004). Heterozygous p53-deficient (+/−) mice develop fewer p53-negative preneoplastic focal liver lesions in response to treatment with diethylnitrosamine than do wild-type (+/+) mice. Cancer Lett. 207, 149–155.15072823
Fuscoe, J.C., Afshari, A.J., George, M.H., DeAngelo, A.B., Tice, R.R., Salman, T., and Allen, J.W. (1996). In vivo genotoxicity of dichloroacetic acid: Evaluation with the mouse peripheral blood micronucleus assay and the single cell gel assay. Environ. Mol. Mutagen. 27, 1–9.
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Giller, S., Le Curieux, F., Erb, F., and Marzin, D. (1997). Comparative genotoxicity of halogenated acetic acids found in drinking water. Mutagenesis 12, 321–328.9379909
Gonzales-Leon, A., Schultz, I.R., Xu, G., and Bull, R.J. (1997). Pharmacokinetics and metabolism of dichloroacetate in the F344 rat after prior administration in drinking water. Toxicol. Appl. Pharmacol. 146, 189–195.9344886
Harrington-Brock, K., Doerr, D.L., and Moore, M.M. (1998). Mutagenicity of three disinfection by-products: Di- and trichloroacetic acid and chloral hydrate in L5178Y/TK^+/−^(−)3.7.2C mouse lymphoma cells. Mutat. Res. 413, 265–276.9651541
Harris, C.C. (1996a). Structure and function of the p53 tumor suppressor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 Tumor suppressor gene: From the basic research laboratory to the clinic – an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture – molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Hildesheim, M.E., Cantor K.P., Lynch C.F., Dosemeci, M., Lubin, J., Alavanja, M., and Craun, G. (1998). Drinking water source and chlorination byproducts. II. Risk of colon and rectal cancers. Epidemiology 9, 29–35.9430265
Hoehn, R.C., Randall, C.W., Goode, R.P., and Shaffer, P.T.B. (1978). Chlorination and water treatment for minimizing trihalomethanes in drinking water. In Water Chlorination: Environmental Impact and Health Effects (R.L. Jolly, G. Hend, and D.H. Hamilton, Jr., Eds.), Vol. 2, pp. 519–535. Ann Arbor Sciences Publishers, Inc., Ann Arbor, MI.
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponsive phenotype. Mol. Carcinog. 30, 99–110.11241757
Lidaka, T., Tsukamoto, T., Totsuka, Y., Hirata, A., Sakai, H., Shirai, N., Yamamoto, M., Wakabayashi, K., Yanai, T., Masegi, T., Donehower, L.A., and Tatematsu, M. (2005). Lack of elevated liver carcinogenicity of aminophenylnorharman in p53-deficient mice. Cancer Lett. 217, 149–159.15617832
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC.
International Agency for Research on Cancer (IARC) (1995). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Dry Cleaning, Some Chlorinated Solvents and Other Industrial Chemicals, Vol. 63. IARC, Lyon, France.
International Agency for Research on Cancer (IARC) (2004). IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans. Some Drinking-water Disinfectants and Contaminants, including Arsenic, Vol. 84. IARC, Lyon, France.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kargalioglu, Y., McMillan, B.J., Minear, R.A., and Plewa, M.J. (2002). Analysis of the cytotoxicity and mutagenicity of drinking water disinfection by-products in Salmonella typhimurium. Teratog. Carcinog. Mutagen. 22, 113–128.11835289
Katz, R., Tai, C.N., Diener, R.M., McConnell, R.F., and Semonick, D.E. (1981). Dichloroacetate, sodium: 3-Month oral toxicity studies in rats and dogs. Toxicol. Appl. Pharmacol. 57, 273–287.7222043
Komulainen, H. (2004). Experimental cancer studies of chlorinated by-products. Toxicology 198, 239–248.15138047
Krasner, S.W., McGuire, M.J., Jacangelo, J.G., Patania, N.L., Reagen, K.M., and Aieta, E.M. (1989). The occurrence of disinfection by-products in US drinking water. J. Am. Water Works Assoc. 81, 41–53.
Kurlemann, G., Paetzke, I., Moller, H., Masur, H., Schuierer, G., Weglage, J., and Koch, H.G. (1995). Therapy of complex I deficiency: Peripheral neuropathy during dichloroacetate therapy. Eur. J. Pediatr. 154, 928–932.8582409
Leavitt, S.A., DeAngelo, A.B., George, M.H., and Ross, J.A. (1997). Assessment of the mutagenicity of dichloroacetic acid in lacI transgenic B6C3F_1_ mouse liver. Carcinogenesis 18, 2101–2106.9395208
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
Lin, E.L., Mattox, J.K., and Daniel, F.B. (1993). Tissue distribution, excretion, and urinary metabolites of dichloroacetic acid in the male Fischer 344 rat. J. Toxicol. Environ. Health 38, 19–32.8421320
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
McGeehin, M.A., Reif, J.S., Becher, J.C., and Mangione, E.J. (1993). Case-control study of bladder cancer and water disinfection methods in Colorado. Am. J. Epidemiol. 138, 492–501.8213753
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Moser, V.C., Phillips, P.M., McDaniel, K.L., and MacPhail, R.C. (1999). Behavioral evaluation of the neurotoxicity produced by dichloroacetic acid in rats. Neurotoxicol. Teratol. 21, 719–731.10560779
National Institute of Environmental Health Sciences (NIEHS) (1999). NIEHS Chemistry Support Services Report No. CHEM04231. Preliminary Chemical Study Report: Plasma Concentrations of Dichloroacetic Acid (DCA) Following Dosed-water Administration and Dermal Application of DCA Using Male and Female FVB/N Mice. NIH Contract No. N01-ES-55395. National Institute of Environmental Health Sciences. Research Triangle Park, NC.
National Toxicology Program (NTP) (1987). Toxicology and Carcinogenesis Studies of Bromodichloromethane (CAS No. 75-27-4) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 321. NIH Publication No. 88-2537. U. S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology Studies of Bromodichloromethane (CAS No. 75-27-4) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal, Drinking Water, and Gavage Studies) and Carcinogenicity Studies of Bromodichloromethane in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water and Gavage Studies). Report Series No. GMM 05. NIH Publication No. 07-4422. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC. (in press)
National Toxicology Program (NTP) (2007b). Toxicology Studies of Sodium Bromate (CAS No. 7789-38-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Sodium Bromate in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Report Series No. GMM 06. NIH Publication No. 07-4423. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Nieuwenhuijsen, M.J., Toledano, M.B., Eaton, N.E., Fawell, J., and Elliott, P. (2000). Chlorination disinfection byproducts in water and their association with adverse reproductive outcomes: A review. Occup. Environ. Med. 57, 73–85.10711274
Parrish, J.M., Austin, E.W., Stevens, D.K., Kinder, D.H., and Bull, R.J. (1996). Haloacetate-induced oxidative damage to DNA in the liver of male B6C3F_1_ mice. Toxicology 110, 103–111.8658551
Plewa, M.J., Kargalioglu, Y., Vankerk, D., Minear, R.A., and Wagner, E.D. (2002). Mammalian cell cytotoxicity and genotoxicity analysis of drinking water disinfection by-products. Environ. Mol. Mutagen. 40, 134–142.12203407
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F_1_ (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Rodriguez, M.J., Serodes, J.B., and Levallois, P. (2004). Behavior of trihalomethanes and haloacetic acids in a drinking water distribution system. Water Res. 38, 4367–4382.15556212
Rook, J.J. (1974). Formation of haloforms during chlorination of natural waters. J. Water Treat. Exam. 23, 234–236.
Rook, J.J. (1980). Possible pathways for the formation of chlorinated degradation products during chlorination of humic acids and resorcinol. In Water Chlorination: Environmental Impact and Health Effects (R.L. Jolly, W.A. Brungs, and R.B. Cumming, Eds.), Vol. 3, pp. 85–98. Ann Arbor Science Publishers Inc., Ann Arbor, MI.
Saghir, S.A., and Schultz, I.R. (2002). Low-dose pharmacokinetics and oral bioavailability of dichloroacetate in naive and GSTAξ-depleted rats. Environ. Health Perspect. 110, 757–763.
Sayato, Y., Nakamuro, K., and Ueno, H. (1987). Mutagenicity of products formed by ozonation of naphthoresorcinol in aqueous solutions. Mutat. Res. 189, 217–222.2959862
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
The Sigma Library of FT-IR Spectra (1986). 1st. ed. (R.J. Keller, Ed.), Spectrum 1-1380C. Sigma Chemical Co., St. Louis, MO.
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG.AC) carrying a v-HA-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Spalding, J.W., French, J.E., Stasiewicz, S., Furedi-Machacek, M., Conner, F., Tice, R.R., and Tennant, R.W. (2000). Response of transgenic mouse lines p53 (+/− ) and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol. Sci. 53, 213–223.10696769
Stacpoole, P.W., Moore, G.W., and Kornhauser, D.M. (1979). Toxicity of chronic dichloroacetate. N. Engl. J. Med. 300, 372.
Stacpoole, P.W., Harwood, H.N., Jr., Cameron, D.F., Curry, S.H., Samuelson, D.A., Cornwell, P.E., and Sauberlich, H.E. (1990). Chronic toxicity to dichloroacetate: Possible relation to thiamine deficiency in rats. Fundam. Appl. Toxicol. 14, 327–337.2318357
Stacpoole, P.W., Henderson, G.N., Yan, Z., Cornett, R., and James, M.O. (1998). Pharmacokinetics, metabolism and toxicology of dichloroacetate. Drug Metab. Rev. 30, 499–539.9710704
Stevens, A.A., Slocum, C.J., Seeger, D.R., and Rebeck, G.G. (1976). Chlorination of organics in drinking water. J. Am. Water Works Assoc. 68, 615–620.
Takizawa, T., Mitsumori, K., Tamura, T., Nasu, M., Ueda, M., Imai, T., and Hirose, M. (2003). Hepatocellular tumor induction in heterozygous p53-deficient CBA mice by a 26-week dietary administration of kojic acid. Toxicol. Sci. 73, 287–293.12700405
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Thompson, K.L., Rosenzweig, B.A., and Sistare, F.D. (1998). An evaluation of the hemizygous transgenic Tg.AC mouse for carcinogenicity testing of pharmaceuticals. II. A genotypic marker that predicts tumorigenic responsiveness. Toxicol. Pathol. 26, 548–555.9715514
Toth, G.P., Kelty, K.C., George, E.L., Read, E.J., and Smith, M.K. (1992). Adverse male reproductive effects following subchronic exposure of rats to sodium dichloroacetate. Fundam. Appl. Toxicol. 19, 57–63.1397802
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
Villanueva, C.M., Fernández, F., Malats, N., Grimalt, J.O., and Kogevinas, M. (2003). Meta-analysis of studies on individual consumption of chlorinated drinking water and bladder cancer. J. Epidemiol. Community Health 57, 166–173.12594192
Weisel, C.P., Kim, H., Haltmeier, P., and Klotz, J.B. (1999). Exposure estimates to disinfection by-products of chlorinated drinking water. Environ Health Perspect. 107, 103–110.9924004
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-HA-ras (TG.AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Yang, H-M., Houser, W.H., and Davis, M.E. (1996). Dichloroacetic acid treatment increases hepatic CYP2E1 in male and female rats. Toxicol. Appl. Pharmacol. 141, 382–388.8975762
Yount, E.A., Felten, S.Y., O’Connor, B.L., Peterson, R.G., Powell, R.S., Yum, M.N., and Harris, R.A. (1982). Comparison of the metabolic and toxic effects of 2-chloropropionate and dichloroacetate. J. Pharmacol. Exp. Ther. 222, 501–508.7097569
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1992). Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ. Mol. Mutagen. 19 (Suppl. 21), 2–141.1541260