# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On September 27, 2005, the draft Report on the toxicology and carcinogenesis studies of dichloroacetic acid received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. J.R. Bucher reviewed the history of the development of genetically modified mouse models in NTP studies. Based on the degrees of acceptance of the various models, results for p53 models are described using the Levels of Evidence of Carcinogenic Activity categories, while conclusions for Tg.AC models are presented descriptively. Dr. G. A. Boorman, NIEHS, introduced the studies of the water disinfection by-product dichloroacetic acid in the Tg.AC and p53 mouse models by various routes of administration. The proposed conclusions were:

Under the conditions of these drinking water studies, there was no evidence of carcinogenic activity of dichloroacetic acid in male or female p53 haploinsufficient mice exposed to 500, 1,000, or 2,000 mg/L for 26 or 41 weeks. The incidences and/or severities of cytoplasmic vacuolization of the hepatocyte were increased in males and females exposed to dichloroacetic acid for 26 or 41 weeks.

Under the conditions of these dermal studies, there were increased incidences of squamous cell papillomas at the site of application in male and female Tg.AC hemizygous mice exposed to 500 mg/kg for 39 weeks. There were dose-related increased incidences of epidermal hyperkeratosis and hyperplasia at the site of application in both male and female mice exposed to dichloroacetic acid for 26 or 39 weeks.

Under the conditions of these drinking water studies, there was an increase in the incidence of alveolar/bronchiolar adenoma in male Tg.AC hemizygous mice exposed to 1,000 mg/L for 41 weeks. There were a few bronchiolar/alveolar carcinomas in males and females exposed to dichloroacetic acid in the drinking water for 26 weeks and a few bronchiolar/alveolar adenomas in females exposed to dichloroacetic acid in the drinking water for 41 weeks.

There were increased incidences and/or severities of cytoplasmic vacuolization of the hepatocyte in male and female Tg.AC hemizygous mice exposed to dichloroacetic acid in the drinking water for 26 or 41 weeks.

The marginally increased incidences of pulmonary adenomas and/or carcinomas compared to the unexposed groups found in both the dermal and drinking water studies at 26, 39, or 41 weeks were considered to be related to dichloroacetic acid exposure.

Dr. Elwell, the first principal reviewer, agreed with the proposed conclusions.

Dr. Crump, the second principal reviewer, thought small body weight differences might have been overemphasized and noted some inconsistencies between text language in the results sections and tables. He inquired if statistical analyses were available for water consumption or nonneoplastic lesion severity.

Dr. Giesy, the third principal reviewer, inquired if more information about thresholds or no-adverse-effect-levels, dose selection, or noncancer endpoints such as hematology were presented in these types of reports.

Dr. Boorman agreed with the reviewers that the dermal studies were not very revealing. He explained that some tables gave in-life observations and some gave histological diagnoses, and these apparent discrepancies would be clarified. He also explained that water consumption was not a very precise measure due to animal behavior and perhaps did not warrant formal statistical analysis.

Dr. Birt noted that the Tg.AC mouse strain had been re-derived some years earlier and asked for more detail of the animal source. She also felt historical control values would be more useful in studies like these with small numbers of animals per group.

Dr. Boorman said that historical control values were generally not kept for nonneoplastic lesions as these did not receive the same degree of histopathologic review.

Dr. Giesy inquired if any conclusion should be made about the evaluation of the mouse models themselves.

Dr. Bucher said that such an overview would probably be made by the full Board of Scientific Counselors once a number of individual studies had been evaluated.

Dr. Elwell moved, and Dr. Vore seconded, that the conclusions be accepted as written with the deletion of the reference to the 26-week dermal study in the final paragraph. The motion was carried with five affirmative votes and one opposing (Dr. Giesy).