# DISCUSSION AND CONCLUSIONS

Dichloroacetic acid is a disinfection by-product of the chlorination of drinking water (Weisel et al., 1999). Dichloroacetic acid is commonly found in the drinking water at concentrations between 5 and 125 µg/L (IARC, 1995). Concentrations of dichloroacetic acid tend to decline with length of time in the distribution system and are higher in the spring and summer (IARC, 2004; Rodriguez et al., 2004). In eight studies, dichloroacetic acid administered in drinking water to male and/or female mice increased the incidences of hepatocellular adenomas and/or carcinomas (IARC, 2004). Dichloroacetic acid at very high doses increased the incidence of hepatocellular carcinomas in the Fisher 344 rat (DeAngelo et al., 1996). In three studies in carcinogen-initiated male and female mice, dichloroacetic acid exposure in the drinking water promoted the formation of hepatocellular carcinomas (IARC, 2004). While dichloroacetic acid is considered carcinogenic to animals (IARC, 2004), carcinogenic activity is usually seen at 1 g/L or greater. As one of the most common haloacetic acids in the drinking water, dichloroacetic acid was nominated to the NTP by the United States Environmental Protection Agency (EPA) for toxicity and carcinogenicity studies in transgenic mice to provide additional information in support of EPA drinking water regulations (40 CFR Part 141). A primary goal was to determine whether transgenic mouse models could prove effective in either hazard identification or in prioritizing which disinfection byproducts warranted further research (Fawell et al., 1997; Boorman et al., 1999). Dichloroacetic acid was considered a good test chemical because of the amount of comparative data available in both standard and carcinogen-initiated mice.

The combination of Tg.AC hemizygous mice and p53 haploinsufficient mice has been suggested as an effective means of identifying chemical carcinogens and assessing potential risk (Tennant et al., 1995). Tg.AC hemizygous mice were reported to respond to tumor promoters, mutagenic chemicals, and nonmutagenic chemicals, while the p53 haploinsufficient mice responded to mutagens within 6 months allowing for the testing of more chemicals within a shorter period of time (Cannon et al., 1997). The NTP evaluated dichloroacetic acid in drinking water because of its common occurrence in drinking water (IARC, 2004). Dermal studies were also included for Tg.AC hemizygous mice since it was reported that tumors usually occurred within 10 weeks of initiation of exposure (Tennant et al., 1995). A visually observable and quantitative tumor response could allow evaluation of either individual chemicals or drinking water by-product mixtures as they might be found with different disinfection processes in a very rapid and cost-effective manner.

In the 26-week study, two of 15 high dose (500 mg/kg) males and two of 15 high dose (500 mg/kg) females had squamous cell papillomas at the site of dermal application. No papillomas were found at the site of application in males or females in the lowest dose groups (31.25 mg/kg) at either 26 or 39 weeks. There was a significant increase in the incidence of papillomas at the site of application in 500 mg/kg males (8/10) and females (6/10) at 39 weeks compared to none in the vehicle controls for males and females. The increase in tumor multiplicity was modest with a mean of 2.6 tumors per tumor-bearing mouse in 500 mg/kg males and 1.4 tumors per tumor-bearing mouse in females at 39 weeks. For comparison, there were approximately 20 tumors per tumor-bearing male or female mouse by 26 weeks in the positive control groups receiving 12-O-tetradecanoylphorbol-13-acetate by dermal application.

The Tg.AC hemizygous mouse is sensitive to dermal injury (Cannon et al., 1997). Following a single full thickness wound, all of the mice develop papillomas with approximately five papillomas per mouse by 10 weeks (Battalora et al., 2001). The dichloroacetic acid exposure caused a dose-related hyperkeratosis and epithelial hyperplasia at the site of application consistent with mild injury. It is unlikely that the papillomas seen at the site of application were secondary to the irritating nature of dichloroacetic acid. The severity of the hyperkeratosis and hyperplasia was generally minimal to mild. In a previous NTP study, rotenone applied to the skin caused hyperplasia, hyperkeratosis, and inflammation at the site of application but failed to increase the incidence of dermal papillomas (Eastin et al., 1998). In a preliminary study using FVB/N mice, dichloroacetic acid was readily absorbed through the skin with dichloroacetic plasma concentrations exceeding 20 µg/mL within 15 minutes after a single dermal application of 500 mg/kg in acetone (NIEHS, 1999). There was no increase in the incidence of dermal papillomas at sites other than the site of application.

The incidences of pulmonary adenomas were statistically increased in male mice in the drinking water study (discussed below), prompting a review of the dermal study for the occurrence of pulmonary adenomas. While not reaching statistical significance, nine pulmonary adenomas (9/150, 6%) occurred in male and female mice exposed to one of three doses at the two time points versus one (1/50, 2%) in the combined male and female control groups. Eight of the pulmonary adenomas occurred in the two highest dermal exposure groups, providing additional evidence that these tumors may be chemical-related. While there were never more than two mice with pulmonary adenomas in any dose group, the small group sizes, the uncommon occurrence of these tumors in untreated mice, and the significance of the occurrence of pulmonary adenomas in the companion drinking water study suggest that dermal dichloroacetic acid exposure may cause or promote pulmonary adenomas in Tg.AC hemizygous mice.

It has been established in eight studies that dichloroacetic acid exposure in drinking water causes hepatocellular tumors in more traditional mouse models (IARC, 2004). In the current Tg.AC hemizygous mouse dermal study, the response was quite weak, with the first dermal papillomas appearing at 25 to 26 weeks and with a very modest response in tumor multiplicity. This suggests that the Tg.AC hemizygous mouse model is not robust enough to determine which haloacetic acids may be tumorigenic in mice.

The 26- and 41-week drinking water studies were conducted in Tg.AC hemizygous mice at dichloroacetic acid exposure concentrations of 500 1,000, or 2,000 mg/L. These drinking water concentrations have been shown to increase liver tumors in male and female B6C3F_1_ mice (Bull et al., 1990; DeAngelo et al., 1999). The hepatocellular adenoma found in one 2,000 mg/L male at 41 weeks was considered unrelated to treatment. There were no hepatocellular adenomas in the females or preneoplastic lesions of the liver in either males or females at 26 or 41 weeks. There was an increased incidence of pulmonary adenoma in males exposed to 1,000 mg/L for 41 weeks (7/10) compared to the incidence of pulmonary adenomas (1/10) in the control group. However, the incidence of pulmonary adenoma did not increase (3/10) at the higher exposure of 2,000 mg/L in the 41-week study. Survival was similar between the 1,000 and 2,000 mg/L groups, but mean body weight was slightly less in the 2,000 mg/L males (mean body weight of 34.4 g) than in the 1,000 mg/L males (mean body weight of 36.4 g). The pulmonary carcinoma in one 1,000 mg/L male at 26 weeks appears to add some support to the finding, as does the occurrence of two pulmonary adenomas in the 2,000 mg/L females in the 41-week study. While the incidences of neoplasms and nonneoplastic lesions were not monotonically dose related, the occurrence of seven uncommon pulmonary adenomas in the 1,000 mg/L group and three in the 2,000 mg/L group were considered related to dichloroacetic acid exposure. The clear positive liver tumor response in several mouse dichloroacetic acid drinking water studies (IARC, 2004) suggests that the Tg.AC mouse is less sensitive than traditional mouse models using the drinking water route of exposure. The pulmonary adenoma response was significant only in the mid-dose group in male mice, and the Tg.AC hemizygous mouse model completely failed to predict the mouse liver tumor response seen with traditional animal models.

Twenty-six- and 41-week drinking water studies were also conducted at the same concentrations (500 1,000, and 2,000 mg/L) in p53 haploinsufficient mice. There were no increased neoplasm incidences in either sex for either study. Two hepatocellular adenomas found in the 500 mg/L males at 41 weeks were considered unrelated to treatment because liver neoplasms were not found at the higher exposures in males. Further, preneoplastic hepatic lesions were not found in any mice at any exposure concentration. In this study, dichloroacetic acid appeared only weakly mutagenic in Salmonella typhimurium consistent with the findings of others (Harrington-Brock et al., 1998; Kargalioglu et al., 2002). Dichloroacetic acid exposure also did not induce micronuclei in peripheral blood of either Tg.AC hemizygous or p53 haploinsufficient mice. Because the p53 haploinsufficient mice are considered unresponsive to nonmutagens, the negative results with this weakly mutagenic chemical may not be surprising. Furthermore, the p53 haploinsufficient mouse is often unresponsive to hepatocarcinogens (Finnberg et al., 2004; Lidaka et al., 2005) but does show increased rates of liver neoplasms with dietary administration of kojic acid (a fungal toxin) (Takizawa et al., 2003). In a companion drinking water study, the p53 haploinsufficient mouse failed to respond to high levels of bromodichloromethane, a multisite, multispecies carcinogen, in the drinking water or by gavage (NTP, 2007a). The data from the current study and from the bromodichloromethane study (NTP, 2007a) suggest that the p53 haploinsufficient mouse is not a suitable model for detecting possible hazardous disinfection byproducts in drinking water. Thus, the NTP’s attempt to find a genetically modified mouse model that could serve as a rapid and reliable screen for assessing the potential toxicity of the different haloacetic acids that occur in the drinking water was not realized. The Tg.AC hemizygous mouse proved to be insensitive to dichloroacetic acid by either dermal or drinking water exposure, while the p53 haploinsufficient mouse model was unresponsive to dichloroacetic acid by drinking water exposure. Since haloacetic acids generally occur in the low µg/L range in the drinking water, it is unlikely that either mouse model evaluated will have much utility in assessing the relative toxicity of the different members of the family of haloacetic acids as they are found in United States water supplies.

## Conclusions

Under the conditions of these drinking water studies, there was no evidence of carcinogenic activity^*^ of dichloroacetic acid in male or female p53 haploinsufficient mice exposed to 0, 500, 1,000, or 2,000 mg/L for 26 or 41 weeks. The incidences and/or severities of cytoplasmic vacuolization of the hepatocyte were increased in males and females exposed to dichloroacetic acid for 26 or 41 weeks.

Under the conditions of these dermal studies, there were increased incidences of squamous cell papillomas at the site of application in male and female Tg.AC hemizygous mice exposed to 500 mg/kg for 39 weeks. There were dose-related increased incidences of epidermal hyperkeratosis and hyperplasia at the site of application in both male and female mice exposed to dichloroacetic acid for 26 or 39 weeks.

Under the conditions of these drinking water studies, there was an increase in the incidence of alveolar/bronchiolar adenoma in male Tg.AC hemizygous mice exposed to 1,000 mg/L for 41 weeks. There were a few bronchiolar/alveolar carcinomas in males and females exposed to dichloroacetic acid in the drinking water for 26 weeks and a few bronchiolar/alveolar adenomas in females exposed to dichloroacetic acid in the drinking water for 41 weeks.

There were increased incidences and/or severities of cytoplasmic vacuolization of the hepatocyte in maleand female Tg.AC hemizygous mice exposed to dichloroacetic acid in the drinking water study for 26 or 41 weeks.

The marginally increased incidences of pulmonary adenomas and/or carcinomas compared to the unexposed groups found in both the dermal and drinking water studies at 39 or 41 weeks were considered to be related to dichloroacetic acid exposure.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 11. A summary of the Technical Reports Review Subcommittee comments and the public discussion on this Report appear on page 13.