# RESULTS

## 26-Week Dermal Study in Tg.AC Hemizygous Mice

### Positive Control Tg.AC Hemizygous Mice

12-O-Tetradecanoylphorbol-13-acetate (TPA) (1.25 µg) was dermally administered to groups of 15 males and 15 females three times weekly. Ninety-three percent of males and all females developed more than 20 skin papillomas each by week 18 (males) or 19 (females) (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 26-week survival probabilities for male and female mice are shown in Table 2. Survival of dosed males and females was similar to that of the vehicle control groups.

### Body Weights and Clinical Findings

The mean body weights of all dosed groups of males and females were similar to those of the vehicle control groups throughout the study (Tables 3 and 4; Figure 1). Clinical findings included papillomas, primarily on the head and in the genital area, in males (5/15, 0/15, 3/15, 6/15) and did not appear to be related to administration of dichloroacetic acid (data not shown). The in-life observations of the papillomas at the site of application were combined with the 39-week study and are shown in Table 10, which appears in the 39-week section of these results.

TABLE 2 Survival of Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 0 | 0 | 2
Natural deaths | 0 | 1 | 1 | 1
Animals surviving to study termination | 13 | 14 | 14 | 12
Percent probability of survival at end of study^a^ | 87 | 93 | 93 | 80
Mean survival (days)^b^ | 176 | 180 | 175 | 160
Survival analysis^c^ | P=0.455 | P=0.984N | P=1.000N | P=0.922
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 0 | 1 | 0 | 0
Natural deaths | 4 | 2 | 1 | 0
Animals surviving to study termination | 11 | 12 | 14 | 15
Percent probability of survival at end of study | 73 | 80 | 93 | 100
Mean survival (days) | 159 | 170 | 177 | 183
Survival analysis | P=0.088N | P=0.922N | P=0.320N | P=0.107N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dosed group is indicated by N.

TABLE 3 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid

Weeks on Study | Vehicle Control | | 31.25 mg/kg | | | 125 mg/kg | | | 500 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.4 | 15 | 22.6 | 101 | 15 | 22.9 | 102 | 15 | 22.5 | 100 | 15
2 | 23.0 | 15 | 23.4 | 102 | 15 | 23.2 | 101 | 15 | 23.4 | 102 | 14
3 | 23.8 | 15 | 24.2 | 102 | 15 | 23.9 | 100 | 15 | 24.6 | 103 | 14
4 | 24.6 | 15 | 25.1 | 102 | 15 | 24.8 | 101 | 15 | 25.2 | 102 | 14
5 | 26.0 | 15 | 26.3 | 101 | 15 | 25.7 | 99 | 15 | 25.7 | 99 | 14
6 | 25.8 | 15 | 26.9 | 104 | 15 | 26.2 | 102 | 15 | 26.7 | 104 | 14
7 | 27.0 | 15 | 27.0 | 100 | 15 | 26.7 | 99 | 15 | 27.2 | 101 | 14
8 | 27.1 | 15 | 27.6 | 102 | 15 | 27.7 | 102 | 15 | 27.5 | 102 | 14
9 | 27.7 | 15 | 28.1 | 101 | 15 | 28.2 | 102 | 15 | 27.6 | 100 | 14
10 | 28.3 | 15 | 28.5 | 101 | 15 | 28.1 | 99 | 15 | 27.9 | 99 | 14
11 | 28.3 | 15 | 28.4 | 100 | 15 | 28.1 | 99 | 15 | 28.4 | 100 | 14
12 | 28.7 | 15 | 28.9 | 101 | 15 | 28.9 | 101 | 15 | 29.1 | 101 | 13
13 | 29.1 | 15 | 29.5 | 101 | 15 | 29.8 | 102 | 14 | 28.9 | 99 | 13
14 | 29.7 | 15 | 29.4 | 99 | 15 | 29.7 | 100 | 14 | 29.9 | 101 | 13
15 | 29.9 | 15 | 30.1 | 101 | 15 | 30.3 | 101 | 14 | 30.4 | 102 | 13
16 | 30.9 | 15 | 30.6 | 99 | 15 | 30.6 | 99 | 14 | 30.7 | 99 | 13
17 | 31.1 | 15 | 31.1 | 100 | 15 | 30.9 | 99 | 14 | 30.8 | 99 | 13
18 | 31.4 | 14 | 31.2 | 99 | 15 | 31.2 | 99 | 14 | 31.5 | 100 | 13
19 | 31.2 | 14 | 31.4 | 101 | 15 | 31.6 | 101 | 14 | 31.1 | 100 | 13
20 | 31.5 | 14 | 31.4 | 100 | 15 | 31.7 | 101 | 14 | 31.7 | 101 | 12
21 | 32.3 | 14 | 31.4 | 97 | 15 | 31.9 | 99 | 14 | 32.3 | 100 | 12
22 | 33.2 | 14 | 32.7 | 99 | 14 | 32.2 | 97 | 14 | 32.2 | 97 | 12
23 | 32.7 | 13 | 31.8 | 97 | 14 | 32.9 | 101 | 14 | 31.4 | 96 | 12
24 | 33.0 | 13 | 32.7 | 99 | 14 | 32.9 | 100 | 14 | 32.3 | 98 | 12
25 | 33.3 | 13 | 32.7 | 98 | 14 | 31.7 | 95 | 14 | 32.4 | 97 | 12
26 | 33.3 | 13 | 32.9 | 99 | 14 | 33.1 | 99 | 14 | 32.1 | 96 | 12
Mean for weeks
1–13 | 26.3 | | 26.7 | 102 | | 26.5 | 101 | | 26.5 | 101
14–26 | 31.8 | | 31.5 | 99 | | 31.6 | 99 | | 31.4 | 99

TABLE 4 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid

Weeks on Study | Vehicle Control | | 31.25 mg/kg | | | 125 mg/kg | | | 500 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.6 | 15 | 19.3 | 99 | 15 | 19.3 | 99 | 15 | 19.0 | 97 | 15
2 | 20.3 | 15 | 19.9 | 98 | 15 | 20.2 | 100 | 15 | 20.1 | 99 | 15
3 | 20.9 | 15 | 20.3 | 97 | 15 | 20.6 | 99 | 15 | 20.6 | 99 | 15
4 | 21.7 | 15 | 21.4 | 99 | 15 | 21.6 | 100 | 15 | 22.0 | 101 | 15
5 | 23.1 | 15 | 22.6 | 98 | 15 | 22.7 | 98 | 15 | 22.9 | 99 | 15
6 | 23.3 | 15 | 22.5 | 97 | 15 | 23.2 | 100 | 15 | 23.3 | 100 | 15
7 | 23.3 | 15 | 22.8 | 98 | 15 | 23.1 | 99 | 15 | 22.4 | 96 | 15
8 | 23.7 | 15 | 22.8 | 96 | 15 | 23.7 | 100 | 15 | 23.4 | 99 | 15
9 | 23.8 | 14 | 23.5 | 99 | 15 | 23.4 | 98 | 15 | 24.0 | 101 | 15
10 | 24.1 | 14 | 23.6 | 98 | 15 | 23.9 | 99 | 15 | 24.0 | 100 | 15
11 | 23.2 | 13 | 24.3 | 105 | 15 | 24.4 | 105 | 15 | 24.7 | 107 | 15
12 | 23.8 | 13 | 24.5 | 103 | 15 | 24.4 | 103 | 15 | 24.5 | 103 | 15
13 | 24.3 | 13 | 24.7 | 102 | 15 | 24.5 | 101 | 15 | 24.6 | 101 | 15
14 | 24.2 | 13 | 24.8 | 103 | 15 | 24.9 | 103 | 15 | 25.3 | 105 | 15
15 | 24.6 | 13 | 25.2 | 102 | 14 | 25.4 | 103 | 14 | 25.1 | 102 | 15
16 | 24.7 | 12 | 25.0 | 101 | 14 | 25.5 | 103 | 14 | 25.6 | 104 | 15
17 | 25.1 | 12 | 24.9 | 99 | 14 | 25.8 | 103 | 14 | 25.5 | 102 | 15
18 | 24.8 | 12 | 25.2 | 102 | 14 | 25.8 | 104 | 14 | 25.7 | 104 | 15
19 | 25.7 | 12 | 25.1 | 98 | 14 | 26.2 | 102 | 14 | 26.4 | 103 | 15
20 | 24.9 | 12 | 25.8 | 104 | 12 | 26.7 | 107 | 14 | 25.9 | 104 | 15
21 | 25.7 | 12 | 26.5 | 103 | 12 | 27.2 | 106 | 14 | 26.3 | 102 | 15
22 | 25.1 | 11 | 26.3 | 105 | 12 | 27.3 | 109 | 14 | 26.6 | 106 | 15
23 | 24.9 | 11 | 26.8 | 108 | 12 | 27.3 | 110 | 14 | 26.5 | 106 | 15
24 | 25.6 | 11 | 27.0 | 106 | 12 | 27.2 | 106 | 14 | 26.8 | 105 | 15
25 | 25.4 | 11 | 26.9 | 106 | 12 | 27.5 | 108 | 14 | 26.4 | 104 | 15
26 | 24.7 | 11 | 26.7 | 108 | 12 | 27.0 | 109 | 14 | 27.0 | 109 | 15
Mean for weeks
1–13 | 22.7 | | 22.5 | 99 | | 22.7 | 100 | | 22.7 | 100
14–26 | 25.0 | | 25.9 | 104 | | 26.5 | 106 | | 26.1 | 104

FIGURE 1 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Dichloroacetic Acid Dermally for 26 Weeks

### Hematology

Hematology data are shown in Table E1. A minimal decrease (2%) in mean cell hemoglobin concentration was statistically identified in the 500 mg/kg males, and a minimal increase (approximately 8%) in platelet counts occurred in the 125 and 500 mg/kg males. The value, in both cases, was not outside what would be considered an acceptable reference limit and was not considered clinically or toxicologically relevant.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the skin, forestomach, liver, and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A1 through A4.

Skin: Squamous cell papillomas occurred at the site of application in one 125 mg/kg male, in two 500 mg/kg males, and in two 500 mg/kg females (Tables 5, A1, and A3). In both males and females, the number of mice bearing papillomas, the time to first appearance, the total number of papillomas, and the mean number of papillomas per mouse (for surviving mice with papillomas) were similar to vehicle controls in the 31.25 and 125 mg/kg groups regardless of the site of the papilloma. Each of these parameters was slightly increased relative to vehicle controls in the 500 mg/kg group. At the site of application, the incidences of epidermal hyperplasia and epidermal hyperkeratosis in the 125 and 500 mg/kg male and female groups were significantly increased. Hyperplasia of the epidermis was characterized by focal thickening of the stratified squamous epithelium. An associated hyperkeratosis was usually present. Squamous cell papillomas of the skin were usually characterized by frond-like projections that radiated from a fibrovascular stalk. However, some papillomas lacked the typical frond-like projections.

TABLE 5 Incidences of Neoplasms and Nonneoplastic Lesions of the Skin in Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
Number Examined Microscopically | 15 | 15 | 15 | 15
Epidermis, Hyperplasia^a^ | 2 (2.5)^b^ | 3 (3.3) | 2 (2.0) | 3 (1.7)
Site of Application, Epidermis, Hyperkeratosis | 2 (1.5) | 7 (1.1) | 15^**^ (1.9) | 14^**^ (2.0)
Site of Application, Epidermis, Hyperplasia | 0 | 2 (1.0) | 11^**^ (1.0) | 13^**^ (1.8)
Squamous Cell Papilloma, Multiple | 0 | 2 | 1 | 2
Squamous Cell Papilloma (includes multiple) | 5 | 5 | 3 | 5
Site of Application, Squamous Cell Papilloma, Multiple | 0 | 0 | 0 | 1
Site of Application, Squamous Cell Papilloma (includes multiple) | 0 | 0 | 1 | 2
Female
Number Examined Microscopically | 15 | 15 | 15 | 15
Hyperkeratosis | 1 (3.0) | 0 | 1 (3.0) | 0
Epidermis, Hyperplasia | 3 (2.7) | 1 (2.0) | 1 (4.0) | 2 (2.5)
Site of Application, Epidermis, Hyperkeratosis | 8 (1.3) | 9 (1.0) | 14^*^ (1.6) | 14^*^ (1.9)
Site of Application, Epidermis, Hyperplasia | 0 | 1 (1–0) | 10^**^ (1.0) | 13^**^ (1.8)
Squamous Cell Papilloma, Multiple | 0 | 3 | 2 | 0
Squamous Cell Papilloma (includes multiple) | 6 | 8 | 8 | 2
Site of Application, Squamous Cell Papilloma | 0 | 0 | 0 | 2

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

Forestomach: The incidences of forestomach squamous cell papilloma were increased in dosed males, especially at 31.25 mg/kg (1/15, 6/15, 3/15, 3/15; Table A1). There were no increases in forestomach papillomas in females (7/15, 6/15, 8/15, 7/15; Table A3). The increase in males was not considered related to treatment because it was not dose-related; there were no increased incidences in males at 39 weeks (7/10, 6/10, 8/10, 7/10; Table A5), and the concurrent 26-week control rate appeared low (in the companion 26-week drinking water study, 4/15 control males had forestomach papillomas; Table B1). In addition, the incidences of forestomach papilloma were not increased in 26- or 39-week females (Tables A3 and A7).

Liver: The absolute and relative liver weights of 125 and 500 mg/kg males and 500 mg/kg females were significantly greater than those of the vehicle controls (Table F1). The incidences of hepatocyte cytoplasmic vacuolization were significantly increased in males and females in the 125 and 500 mg/kg groups, and the average severity generally increased with increasing dose (Tables 6, A2, and A4). Hepatocyte cytoplasmic vacuolization was characterized by poorly demarcated cytoplasmic clear spaces that lacked distinct borders and that were partially separated by irregular strands of eosinophilic cytoplasm. This change was considered consistent with cytoplasmic glycogen accumulation. The vacuole area sometimes displayed light basophilic stippling, a discoloration that was observed only occasionally in controls but more frequently in the treated animals. The pattern of accumulation tended to be centrilobular but as severity increased involved more of the hepatocytes within the lobules. Hepatocyte vacuolization was graded according to the following criteria: minimal vacuolization was slight and consisted of small, poorly demarcated, usually perinuclear, clear spaces in the cytoplasm that were barely visible at low magnification. Mild vacuolization tended to be more prominent at low magnification; vacuoles were irregular and coalesced but did not distend the cytoplasm and were not associated with increase in cell size. Moderate vacuolization was characterized by vacuoles that clearly coalesced and the hepatocyte cytoplasm was expanded one and a half to twice the normal cell size compared to that of the controls. Hepatocyte nuclei were typically centrally located. Marked hepatocyte vacuolization consisted of an exaggeration of the features described above with an increase in hepatocyte size that was approximately two or more times normal size. Hepatocyte vacuolization was frequently accompanied by the presence of discrete clear cytoplasmic vacuoles consistent with cytoplasmic lipid accumulation and diagnosed as fatty change.

Kidney: The incidence of nephropathy was significantly increased in the 500 mg/kg males; however, the severity was similar to that of the vehicle controls (Tables 6 and A2). Nephropathy consisted of a spectrum of changes that occurred alone or in combination and included small clusters of tubules with cytoplasmic basophilia (regeneration), tubular dilatation and proteinaceous casts, and interstitial mononuclear inflammatory cell infiltration.

TABLE 6 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
Liver^a^ | 15 | 15 | 15 | 15
Hepatocyte, Vacuolization Cytoplasmic^b^ | 3 (1.0)^c^ | 4 (1.0) | 14^**^(1.8) | 15^**^(2.8)
Kidney | 15 | 15 | 15 | 15
Nephropathy | 7 (1.0) | 7 (1.0) | 11 (1.0) | 13^*^ (1.0)
Female
Liver | 15 | 15 | 15 | 15
Hepatocyte, Vacuolization Cytoplasmic | 6 (1.2) | 4 (1.0) | 14^**^(2.1) | 15^**^(3.3)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 39-Week Dermal Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 39-week survival probabilities for male and female mice are shown in Table 7. Survival of dosed males and females was similar to that of the vehicle controls.

### Body Weights and Clinical Findings

The mean body weights of the 31.25 mg/kg males were less than those of the vehicle controls after week 22, and those of 500 mg/kg males were less than those of the vehicle controls after week 21; although mean body weights of 125 mg/kg males were less from weeks 28 to 38, the mean body weight was similar to that of the vehicle controls at the end of the study (Figure 2 and Table 8). The mean body weights of 500 mg/kg females were greater than those of the vehicle controls after week 17, and the mean body weights of the 31.25 and 125 mg/kg groups were greater at the end of the study (Figure 2 and Table 9).

Chemical-related clinical findings included increased observations of papillomas at the site of application in 125 and 500 mg/kg males (vehicle control, 0/10; 31.25 mg/kg, 0/10; 125 mg/kg, 2/10; 500 mg/kg, 8/10) and females (0/10, 0/10, 1/10, 5/10). While vehicle control animals did not have papillomas at the site of application, papillomas were observed in these groups at nonapplication sites (males: 9/10, 4/10, 7/10, 7/10; females: 8/10, 6/10, 8/10, 7/10).

Because the 26- and 39-week studies were conducted concurrently, papilloma formation data were combined and analyzed using the model of Dunson et al. (2000). For males and females, there were significant dose-related trends in time to first papilloma and in the number of papillomas per animal (Table 10). Furthermore, the time to first tumor in the 500 mg/kg group was significantly less than in the control group for males and females.

TABLE 7 Survival of Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 3 | 1 | 2
Natural deaths | 0 | 1 | 1 | 1
Animals surviving to study termination | 9 | 6 | 8 | 7
Percent probability of survival at end of study^a^ | 90 | 60 | 80 | 70
Mean survival (days)^b^ | 268 | 236 | 263 | 256
Survival analysis^c^ | P=0.980 | P=0.275 | P=1.000 | P=0.578
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 2 | 3 | 2 | 2
Natural deaths | 0 | 2 | 2 | 0
Animals surviving to study termination | 8 | 5 | 6 | 8
Percent probability of survival at end of study | 80 | 50 | 60 | 80
Mean survival (days) | 246 | 222 | 251 | 249
Survival analysis | P=0.618N | P=0.356 | P=0.679 | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dosed group is indicated by N.

FIGURE 2 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Dichloroacetic Acid Dermally for 39 Weeks

TABLE 8 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid

Weeks on Study | Vehicle Control | | 31.25 mg/kg | | | 125 mg/kg | | | 500 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.9 | 10 | 22.7 | 99 | 10 | 22.6 | 99 | 10 | 22.7 | 99 | 10
2 | 23.1 | 10 | 23.4 | 101 | 10 | 23.4 | 101 | 10 | 23.5 | 102 | 10
3 | 24.2 | 10 | 23.8 | 98 | 10 | 24.4 | 101 | 10 | 24.1 | 100 | 10
4 | 25.2 | 10 | 24.7 | 98 | 10 | 25.0 | 99 | 10 | 25.1 | 100 | 10
5 | 25.8 | 10 | 25.0 | 97 | 10 | 25.5 | 99 | 10 | 25.9 | 100 | 10
6 | 27.1 | 10 | 26.2 | 97 | 10 | 26.3 | 97 | 10 | 26.2 | 97 | 10
7 | 27.0 | 10 | 25.9 | 96 | 10 | 26.3 | 97 | 10 | 27.1 | 100 | 10
8 | 28.5 | 10 | 27.4 | 96 | 10 | 27.2 | 95 | 10 | 27.4 | 96 | 10
9 | 29.1 | 10 | 27.6 | 95 | 10 | 28.1 | 97 | 10 | 27.6 | 95 | 10
10 | 29.2 | 10 | 27.8 | 95 | 10 | 28.0 | 96 | 10 | 28.2 | 97 | 10
11 | 29.2 | 10 | 28.5 | 98 | 10 | 28.8 | 99 | 10 | 28.6 | 98 | 10
12 | 29.8 | 10 | 28.3 | 95 | 10 | 28.9 | 97 | 10 | 28.9 | 97 | 10
13 | 30.8 | 10 | 29.2 | 95 | 10 | 29.7 | 96 | 10 | 29.5 | 96 | 10
14 | 30.8 | 10 | 29.3 | 95 | 10 | 29.5 | 96 | 10 | 29.7 | 96 | 10
15 | 31.3 | 10 | 30.2 | 97 | 10 | 30.7 | 98 | 10 | 30.1 | 96 | 10
16 | 31.9 | 10 | 29.9 | 94 | 10 | 29.6 | 93 | 10 | 30.4 | 95 | 10
17 | 31.5 | 10 | 30.9 | 98 | 10 | 31.1 | 99 | 10 | 30.4 | 97 | 10
18 | 32.4 | 10 | 30.7 | 95 | 10 | 31.7 | 98 | 10 | 30.6 | 94 | 10
19 | 32.2 | 10 | 30.9 | 96 | 9 | 31.2 | 97 | 10 | 31.6 | 98 | 10
20 | 33.0 | 10 | 31.7 | 96 | 9 | 31.9 | 97 | 10 | 31.8 | 96 | 10
21 | 33.3 | 10 | 31.6 | 95 | 9 | 33.2 | 100 | 10 | 32.0 | 96 | 10
22 | 33.3 | 10 | 31.9 | 96 | 9 | 33.1 | 99 | 10 | 31.3 | 94 | 10
23 | 34.7 | 10 | 32.2 | 93 | 9 | 32.5 | 94 | 10 | 31.6 | 91 | 10
24 | 34.4 | 10 | 32.1 | 93 | 8 | 33.4 | 97 | 10 | 32.2 | 94 | 10
25 | 33.9 | 10 | 31.4 | 93 | 8 | 33.2 | 98 | 10 | 32.0 | 94 | 10
26 | 34.0 | 10 | 32.4 | 95 | 8 | 34.0 | 100 | 10 | 32.1 | 94 | 9
27 | 34.5 | 10 | 32.4 | 94 | 8 | 32.6 | 95 | 10 | 31.5 | 91 | 9
28 | 35.3 | 10 | 31.9 | 90 | 8 | 32.1 | 91 | 10 | 32.2 | 91 | 9
29 | 36.4 | 10 | 32.2 | 89 | 8 | 33.4 | 92 | 10 | 32.2 | 89 | 9
30 | 36.2 | 10 | 31.1 | 86 | 8 | 33.4 | 92 | 10 | 32.6 | 90 | 9
31 | 36.6 | 10 | 31.5 | 86 | 8 | 33.0 | 90 | 10 | 32.2 | 88 | 9
32 | 37.2 | 9 | 32.6 | 88 | 7 | 34.2 | 92 | 9 | 33.0 | 89 | 9
33 | 38.2 | 9 | 33.0 | 86 | 7 | 34.3 | 90 | 9 | 32.3 | 85 | 9
34 | 38.2 | 9 | 33.8 | 89 | 6 | 35.0 | 92 | 8 | 34.2 | 90 | 8
35 | 38.3 | 9 | 33.3 | 87 | 6 | 34.9 | 91 | 8 | 33.6 | 88 | 8
36 | 39.1 | 9 | 33.6 | 86 | 6 | 34.1 | 87 | 8 | 33.8 | 86 | 7
37 | 38.5 | 9 | 34.1 | 89 | 6 | 35.8 | 93 | 8 | 34.2 | 89 | 7
38 | 38.2 | 9 | 33.8 | 89 | 6 | 36.0 | 94 | 8 | 34.1 | 89 | 7
39 | 37.4 | 9 | 33.9 | 91 | 6 | 36.5 | 98 | 8 | 34.3 | 92 | 7
Mean for weeks
1–13 | 27.1 | | 26.2 | 97 | | 26.5 | 98 | | 26.5 | 98
14–39 | 35.0 | | 32.0 | 91 | | 33.1 | 95 | | 32.2 | 92

TABLE 9 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid

Weeks on Study | Vehicle Control | | 31.25 mg/kg | | | 125 mg/kg | | | 500 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.5 | 10 | 19.9 | 102 | 10 | 19.7 | 101 | 10 | 19.7 | 101 | 10
2 | 19.8 | 10 | 19.8 | 100 | 10 | 19.9 | 101 | 10 | 20.2 | 102 | 10
3 | 19.8 | 10 | 20.5 | 104 | 10 | 20.9 | 106 | 10 | 20.2 | 102 | 10
4 | 21.7 | 10 | 21.6 | 100 | 9 | 22.0 | 101 | 10 | 22.0 | 101 | 10
5 | 22.8 | 10 | 20.0 | 88 | 9 | 22.4 | 98 | 10 | 21.9 | 96 | 10
6 | 23.1 | 10 | 22.7 | 98 | 9 | 23.1 | 100 | 10 | 23.4 | 101 | 10
7 | 23.1 | 10 | 22.4 | 97 | 9 | 22.9 | 99 | 10 | 22.1 | 96 | 10
8 | 23.2 | 10 | 22.8 | 98 | 9 | 23.2 | 100 | 10 | 20.9 | 90 | 10
9 | 23.3 | 10 | 23.1 | 99 | 9 | 23.6 | 101 | 10 | 23.7 | 102 | 9
10 | 24.0 | 10 | 23.1 | 96 | 9 | 23.5 | 98 | 10 | 23.8 | 99 | 9
11 | 23.9 | 10 | 23.5 | 98 | 9 | 24.1 | 101 | 9 | 24.0 | 100 | 9
12 | 24.4 | 10 | 24.2 | 99 | 9 | 25.1 | 103 | 9 | 24.7 | 101 | 9
13 | 24.7 | 10 | 24.3 | 98 | 9 | 24.8 | 100 | 9 | 25.2 | 102 | 9
14 | 24.6 | 10 | 24.1 | 98 | 9 | 25.0 | 102 | 9 | 25.4 | 103 | 9
15 | 25.4 | 10 | 24.2 | 95 | 9 | 25.2 | 99 | 9 | 25.7 | 101 | 9
16 | 24.8 | 10 | 24.5 | 99 | 9 | 25.2 | 102 | 9 | 26.0 | 105 | 9
17 | 25.5 | 10 | 24.3 | 95 | 8 | 25.6 | 100 | 9 | 26.1 | 102 | 9
18 | 25.3 | 9 | 24.7 | 98 | 8 | 26.0 | 103 | 9 | 26.7 | 106 | 9
19 | 25.1 | 9 | 24.7 | 98 | 8 | 25.0 | 100 | 9 | 26.7 | 106 | 9
20 | 24.9 | 9 | 25.3 | 102 | 8 | 25.0 | 100 | 9 | 26.9 | 108 | 9
21 | 25.0 | 9 | 25.7 | 103 | 8 | 26.7 | 107 | 9 | 27.6 | 110 | 9
22 | 25.9 | 8 | 25.4 | 98 | 8 | 26.5 | 102 | 9 | 28.7 | 111 | 9
23 | 26.3 | 8 | 25.7 | 98 | 8 | 26.8 | 102 | 9 | 29.0 | 110 | 9
24 | 26.2 | 8 | 25.8 | 99 | 8 | 27.1 | 103 | 9 | 29.4 | 112 | 9
25 | 26.7 | 8 | 25.7 | 96 | 8 | 26.9 | 101 | 9 | 29.6 | 111 | 9
26 | 26.9 | 8 | 26.0 | 97 | 8 | 27.0 | 100 | 9 | 29.3 | 109 | 9
27 | 26.6 | 8 | 26.4 | 99 | 8 | 27.1 | 102 | 9 | 30.5 | 115 | 9
28 | 27.2 | 8 | 26.4 | 97 | 8 | 27.2 | 100 | 9 | 31.0 | 114 | 9
29 | 27.3 | 8 | 27.1 | 99 | 8 | 27.3 | 100 | 9 | 31.6 | 116 | 9
30 | 28.0 | 8 | 26.7 | 95 | 8 | 27.9 | 100 | 9 | 31.0 | 111 | 9
31 | 27.6 | 8 | 26.6 | 96 | 8 | 28.0 | 101 | 9 | 31.2 | 113 | 9
32 | 27.5 | 8 | 27.3 | 99 | 7 | 28.0 | 102 | 9 | 31.4 | 114 | 9
33 | 27.5 | 8 | 27.7 | 101 | 7 | 28.6 | 104 | 9 | 32.0 | 116 | 9
34 | 27.0 | 8 | 27.0 | 100 | 7 | 27.9 | 103 | 9 | 32.6 | 121 | 9
35 | 26.5 | 8 | 27.1 | 102 | 7 | 28.3 | 107 | 9 | 32.2 | 122 | 9
36 | 27.1 | 8 | 26.3 | 97 | 7 | 28.6 | 106 | 9 | 32.6 | 120 | 9
37 | 27.4 | 8 | 27.3 | 100 | 6 | 28.4 | 104 | 9 | 34.5 | 126 | 8
38 | 27.2 | 8 | 28.0 | 103 | 5 | 27.3 | 100 | 9 | 33.3 | 122 | 8
39 | 25.7 | 8 | 27.8 | 108 | 5 | 29.9 | 116 | 7 | 35.3 | 137 | 8
Mean for weeks
1–13 | 22.6 | | 22.1 | 98 | | 22.7 | 100 | | 22.4 | 99
14–39 | 26.4 | | 26.1 | 99 | | 27.0 | 102 | | 29.9 | 113

TABLE 10 Skin Papilloma Formation at the Site of Application in Tg.AC Hemizygous Mice in the 26- and 39-Week Dermal Studies of Dichloroacetic Acid^a^

Dose (mg/kg) | Number (Percent) with Papilloma^b^ | Time to Initial Papilloma Occurrence for All Animals in Group^c^ (Week) | | Distribution of Number of Papillomas per Animal^d^ Quantiles | | | Test of Dunson et al. Model^e^
Dose (mg/kg) | Number (Percent) with Papilloma^b^ | First | Median | 10th | 50th | 90th | γ_1_ | γ_2_
Male
0 | 0 (0.0%) | >39 | >39 | 0 | 0 | 0
31.25 | 1 (4.0%) | 18 | >39 | 0 | 0 | 0 | NT | NT
125 | 1 (4.0%) | 28 | >39 | 0 | 0 | 0 | NT | NT
500 | 10 (40.0%) | 16 | >39 | 0 | 0 | 4 | * | NT
Trend | | | | | | | * | *
Positive Control^f^ | 14 (99.8%) | 9 | 11 | 20+ | 20+ | 20+ | * | NT
Female
0 | 0 (0.0%) | >39 | >39 | 0 | 0 | 0
31.25 | 0 (0.0%) | >39 | >39 | 0 | 0 | 0 | NT | NT
125 | 2 (8.0%) | 27 | >39 | 0 | 0 | 0 | NT | NT
500 | 10 (40.0%) | 16 | >39 | 0 | 0 | 2 | * | NT
Trend | | | | | | | * | *
Positive Control | 15 (100.0%) | 9 | 11 | 20+ | 20+ | 20+ | * | NT

a 25 males and 25 females initially in each dose group; 15 males and 15 females initially in positive control group

b Percent is Poly-3 adjusted rate and reflects whether the animal ever had a confirmed papilloma at any point in the study.

c If the first papilloma was observed at the terminal sacrifice, it was assigned a time to first occurrence of the sacrifice time. For groups in which fewer than half of the animals had papillomas, the median time to initial occurrence is >39 weeks.

d Quantiles are based on all animals in a group, whether removed before the end of study or not. For example, a value of 4 for the 90th quantile implies that 90% of the animals in the study had 4 papillomas or fewer at the end of the study (or at removal from study).

e The Dunson et al. (2000) model accounts for latency (γ_1_ and multiplicity (γ_2_) in the rate of occurrence. NT (No Test) indicates that these data do not support a pairwise test. * (P≤0.05) indicates a significant trend or a significant difference from the vehicle control group.

f 100 µL of 1.25 µg 12-O-tetradecanoylphorbol-13-acetate per 100 mL acetone administered three times per week

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the skin, liver, kidney, thymus, and testes. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A5 through A8.

Skin: At the site of application, the incidences of epidermal hyperplasia were significantly increased in the 125 and 500 mg/kg males and the 500 mg/kg females (Tables 11, A6, and A8). Epidermal hyperkeratosis occurred in all groups of males and females, with significantly increased incidences in 31.25 and 125 mg/kg males and 500 mg/kg males and females. The incidences of squamous cell papillomas at the site of application were significantly increased in the 500 mg/kg males and females (Tables 11, A5, and A7).

Liver: There was a dose-related increase in the mean severity of hepatocyte cytoplasmic vacuolization in males and females; the severity increased in dosed groups from minimal at 31.25 mg/kg, mild at 125 mg/kg, to moderate at 500 mg/kg (Table 12). The incidence of hepatocyte necrosis was significantly increased in the 500 mg/kg males.

Kidney: The incidences of nephropathy were significantly increased in all dosed groups of males; however, the severities of nephropathy in the dosed groups were similar to that of the vehicle controls (Table 12).

TABLE 11 Incidences of Neoplasms and Nonneoplastic Lesions of the Skin in Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10
Site of Application
Epidermis, Hyperkeratosis^a^ | 2 (1.0)^b^ | 8^*^ (1.3) | 9^**^ (1.6) | 10^**^ (2.1)
Epidermis, Hyperplasia | 0 | 0 | 8^**^ (1.3) | 9^**^ (2.2)
Squamous Cell Papilloma, Multiple | 0 | 0 | 1 | 6^**^
Squamous Cell Papilloma (includes multiple) | 0 | 0 | 2 | 8^**^
Other than Site of Application
Squamous Cell Papilloma, Multiple | 6 | 4 | 7 | 2
Squamous Cell Papilloma (includes multiple) | 8 | 4 | 7 | 9
Female
Number Examined Microscopically | 10 | 10 | 10 | 10
Site of Application
Epidermis, Hyperkeratosis | 5 (1.4) | 8 (1.0) | 9 (1.4) | 10^*^ (1.0)
Epidermis, Hyperplasia | 0 | 0 | 3 (1.3) | 6^**^ (1.3)
Squamous Cell Papilloma, Multiple | 0 | 0 | 0 | 3
Squamous Cell Papilloma (includes multiple) | 0 | 0 | 0 | 6^**^
Other than Site of Application
Squamous Cell Papilloma, Multiple | 5 | 2 | 4 | 4
Squamous Cell Papilloma (includes multiple) | 7 | 5 | 5 | 7

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

TABLE 12 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
Liver^a^ | 10 | 10 | 10 | 10
Hepatocyte, Necrosis^b^ | 1 (1.0)^c^ | 0 | 2 (1.0) | 6^*^ (1.0)
Hepatocyte, Vacuolization Cytoplasmic | 9 (1.1) | 7 (1.3) | 8 (2.3) | 10 (3.0)
Kidney | 10 | 10 | 10 | 10
Nephropathy | 2 (1.0) | 7^*^ (1.0) | 7^*^ (1.0) | 8^*^ (1.0)
Thymus | 9 | 10 | 10 | 9
Atrophy | 0 | 3 (2.7) | 1 (3.0) | 4^*^ (2.8)
Testes | 10 | 10 | 10 | 10
Germinal Epithelium, Degeneration | 3 (3.7) | 2 (3.0) | 1 (2.0) | 8^*^ (2.3)
Female
Liver | 10 | 10 | 10 | 10
Hepatocyte, Vacuolization Cytoplasmic | 7 (1.0) | 6 (1.2) | 8 (2.0) | 10 (2.7)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

Thymus: There was a significantly increased incidence of atrophy in 500 mg/kg males, but the increase was not considered dose related (Table 12).

Testes: The incidence of germinal epithelium degeneration in 500 mg/kg males was significantly increased; the increased incidence was not dose related (Table 12).

## 26-Week Drinking Water Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 26-week survival probabilities for male and female mice are shown in Table 13. Survival of all exposed groups of males was similar to that of the control group. Survival of the 500 and 2,000 mg/L females was significantly lower than that of the control group.

### Body Weights, Water and Compound Consumption, and Clinical Findings

The mean body weights of 500 mg/L males were greater than those of the controls after week 17, and those of 1,000 mg/L males were greater after week 21 (Table 14; Figure 3). The mean body weights of 1,000 and 2,000 mg/L females were generally less than those of the controls after weeks 16 and 15, respectively (Table 15; Figure 3). Water consumption by 2,000 mg/L males and females was less than that by the controls throughout most of the study (Tables H1 and H2). Drinking water concentrations of 500, 1,000, and 2,000 mg/L resulted in average daily doses of approximately 75, 145, and 240 mg dichloroacetic acid/kg body weight to males and 100, 180, and 300 mg/kg to females.

TABLE 13 Survival of Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 1 | 2 | 4 | 1
Animals surviving to study termination | 14 | 13 | 11 | 14
Percent probability of survival at end of study^a^ | 93 | 87 | 73 | 93
Mean survival (days)^b^ | 169 | 161 | 167 | 173
Survival analysis^c^ | P=1.000N | P=0.984 | P=0.384 | P=1.000N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 0 | 4 | 1 | 4
Natural deaths | 0 | 3 | 1 | 1
Animals surviving to study termination | 15 | 8 | 13 | 10
Percent probability of survival at end of study | 100 | 53 | 87 | 67
Mean survival (days) | 177 | 148 | 166 | 155
Survival analysis | P=0.256 | P=0.009 | P=0.464 | P=0.050

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

### Hematology

Hematology data are shown in Table E2. No changes that were considered clinically or toxicologically relevant occurred.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the salivary gland, lung, liver, skin, and forestomach. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables B1 through B4.

Salivary gland: The incidences of carcinoma were slightly increased in 1,000 and 2,000 mg/L males (0/0, 0/0, 1/1, 1/1; Table B1). No adenomas were observed in this study.

Lung: An alveolar/bronchiolar carcinoma was present in one 1,000 mg/L male, one 500 mg/L female, and one 2,000 mg/L female (males: 0/15, 0/15, 1/15, 0/15; females: 0/15, 1/15, 0/15, 1/15; Tables B1 and B3).

Liver: The incidences of hepatocyte cytoplasmic vacuolization were significantly increased in all exposed groups of males and in 1,000 and 2,000 mg/L females; in both sexes, the average severity of hepatocyte cytoplasmic vacuolization increased with increasing exposure concentration (Tables 16, B2, and B4). Hepatocyte cytoplasmic vacuolization was morphologically similar to that previously described in the 26-week dermal study.

TABLE 14 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 21.2 | 15 | 21.9 | 103 | 15 | 21.7 | 102 | 15 | 22.0 | 104 | 15
2 | 22.5 | 15 | 22.8 | 101 | 15 | 23.2 | 103 | 15 | 22.8 | 101 | 15
3 | 23.7 | 15 | 24.3 | 103 | 15 | 25.1 | 106 | 15 | 24.8 | 105 | 15
4 | 25.4 | 15 | 26.3 | 104 | 15 | 26.4 | 104 | 15 | 26.1 | 103 | 15
5 | 26.4 | 15 | 27.4 | 104 | 15 | 27.3 | 103 | 15 | 27.0 | 102 | 15
6 | 27.1 | 15 | 27.7 | 102 | 15 | 27.4 | 101 | 15 | 27.8 | 103 | 15
7 | 27.8 | 15 | 28.2 | 101 | 15 | 28.1 | 101 | 15 | 27.9 | 100 | 15
8 | 28.4 | 15 | 29.0 | 102 | 15 | 29.1 | 103 | 15 | 28.5 | 100 | 15
9 | 28.8 | 15 | 29.3 | 102 | 15 | 30.0 | 104 | 15 | 28.9 | 100 | 15
10 | 28.6 | 15 | 30.2 | 106 | 14 | 29.8 | 104 | 15 | 28.8 | 101 | 15
11 | 29.7 | 14 | 30.8 | 104 | 14 | 30.6 | 103 | 15 | 29.9 | 101 | 15
12 | 30.8 | 14 | 31.3 | 102 | 13 | 30.8 | 100 | 15 | 30.9 | 100 | 15
13 | 31.0 | 14 | 31.6 | 102 | 13 | 31.6 | 102 | 15 | 31.2 | 101 | 15
14 | 31.2 | 14 | 32.0 | 103 | 13 | 31.6 | 101 | 15 | 31.3 | 100 | 15
15 | 31.5 | 14 | 32.2 | 102 | 13 | 31.6 | 100 | 15 | 31.5 | 100 | 15
16 | 31.3 | 14 | 32.5 | 104 | 13 | 31.8 | 102 | 15 | 31.6 | 101 | 15
17 | 31.5 | 14 | 33.4 | 106 | 13 | 31.9 | 101 | 15 | 32.1 | 102 | 15
18 | 31.7 | 14 | 33.7 | 106 | 13 | 32.3 | 102 | 15 | 32.0 | 101 | 15
19 | 32.5 | 14 | 34.7 | 107 | 13 | 33.4 | 103 | 15 | 33.3 | 103 | 15
20 | 32.8 | 14 | 35.3 | 108 | 13 | 32.8 | 100 | 15 | 32.8 | 100 | 14
21 | 33.2 | 14 | 35.7 | 108 | 13 | 31.7 | 96 | 15 | 33.1 | 100 | 14
22 | 33.6 | 14 | 35.7 | 106 | 13 | 35.7 | 106 | 11 | 33.3 | 99 | 14
23 | 33.4 | 14 | 35.4 | 106 | 13 | 35.7 | 107 | 11 | 33.9 | 102 | 14
24 | 33.8 | 14 | 35.4 | 105 | 13 | 35.9 | 106 | 11 | 33.7 | 100 | 14
25 | 34.5 | 14 | 35.5 | 103 | 13 | 36.5 | 106 | 11 | 34.1 | 99 | 14
Mean for weeks
1–13 | 27.0 | | 27.8 | 103 | | 27.8 | 103 | | 27.4 | 101
14–25 | 32.6 | | 34.3 | 105 | | 33.4 | 102 | | 32.7 | 100

TABLE 15 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.7 | 15 | 18.7 | 100 | 15 | 18.8 | 101 | 15 | 19.0 | 102 | 15
2 | 18.9 | 15 | 19.2 | 102 | 15 | 19.6 | 104 | 15 | 19.3 | 102 | 15
3 | 19.4 | 15 | 20.5 | 106 | 15 | 20.5 | 106 | 15 | 20.5 | 106 | 15
4 | 21.5 | 15 | 21.3 | 99 | 15 | 21.7 | 101 | 15 | 21.2 | 99 | 15
5 | 22.3 | 15 | 22.2 | 100 | 15 | 22.2 | 100 | 15 | 21.9 | 98 | 15
6 | 22.8 | 15 | 22.2 | 97 | 15 | 22.8 | 100 | 15 | 21.9 | 96 | 15
7 | 22.9 | 15 | 22.2 | 97 | 14 | 23.1 | 101 | 15 | 22.4 | 98 | 15
8 | 24.0 | 15 | 23.2 | 97 | 14 | 23.7 | 99 | 15 | 22.8 | 95 | 15
9 | 24.3 | 15 | 24.3 | 100 | 14 | 24.4 | 100 | 15 | 23.2 | 96 | 15
10 | 24.2 | 15 | 24.9 | 103 | 14 | 24.4 | 101 | 14 | 22.6 | 93 | 15
11 | 24.6 | 15 | 24.9 | 101 | 14 | 25.1 | 102 | 14 | 23.1 | 94 | 13
12 | 25.1 | 15 | 24.7 | 98 | 14 | 24.8 | 99 | 14 | 23.9 | 95 | 13
13 | 25.5 | 15 | 25.2 | 99 | 14 | 24.8 | 97 | 14 | 24.1 | 95 | 13
14 | 25.5 | 15 | 25.9 | 102 | 13 | 25.2 | 99 | 14 | 24.6 | 97 | 13
15 | 26.0 | 15 | 26.2 | 101 | 13 | 25.3 | 97 | 14 | 24.9 | 96 | 13
16 | 26.6 | 15 | 26.5 | 100 | 13 | 25.3 | 95 | 14 | 25.0 | 94 | 13
17 | 27.3 | 15 | 27.2 | 100 | 12 | 25.3 | 93 | 14 | 24.7 | 91 | 13
18 | 27.3 | 15 | 27.4 | 100 | 11 | 25.7 | 94 | 14 | 24.6 | 90 | 12
19 | 27.6 | 15 | 29.6 | 107 | 11 | 25.8 | 94 | 14 | 25.2 | 91 | 12
20 | 28.0 | 15 | 30.1 | 108 | 10 | 27.2 | 97 | 13 | 25.2 | 90 | 12
21 | 29.1 | 15 | 29.7 | 102 | 10 | 27.2 | 94 | 13 | 25.2 | 87 | 12
22 | 29.4 | 15 | 28.7 | 98 | 10 | 27.4 | 93 | 13 | 25.9 | 88 | 11
23 | 29.9 | 15 | 30.5 | 102 | 9 | 28.2 | 94 | 13 | 25.9 | 87 | 11
24 | 30.2 | 15 | 30.5 | 101 | 9 | 28.4 | 94 | 13 | 26.7 | 88 | 11
25 | 30.7 | 15 | 32.2 | 105 | 8 | 28.8 | 94 | 13 | 28.0 | 91 | 10
Mean for weeks
1–13 | 22.6 | | 22.6 | 100 | | 22.8 | 101 | | 22.0 | 97
14–25 | 28.1 | | 28.7 | 102 | | 26.7 | 95 | | 25.5 | 91

FIGURE 3 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Dichloroacetic Acid in Drinking Water for 26 Weeks

Skin: There was an increased incidence of epidermal hyperplasia in 2,000 mg/L females, but the increase was not statistically significant (Tables 16 and B4). The incidences of squamous cell papilloma in exposed groups of mice were similar to those in the controls (Tables B1 and B3). Hyperplasia was morphologically similar to that previously described in the 26-week dermal study.

Forestomach: There were slight, though not statistically significant, increases in the incidences of epithelial hyperplasia in 2,000 mg/L males and 500 mg/L females (Tables 16, B2, and B4). The incidence of epithelial hyperkeratosis was significantly increased in 500 mg/L females. The incidences of squamous cell papilloma in exposed groups of mice were similar to those in the controls (Tables B1 and B3).

TABLE 16 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Liver^a^ | 15 | 15 | 15 | 15
Hepatocyte, Vacuolization Cytoplasmic^b^ | 7 (1.0)^c^ | 13^*^ (1.8) | 15^**^ (2.7) | 15^**^ (3.7)
Stomach, Forestomach | 15 | 15 | 15 | 15
Epithelium, Hyperkeratosis | 0 | 0 | 1 (2.0) | 1 (2.0)
Epithelium, Hyperplasia | 2 (1.0) | 4 (2.0) | 3 (2.0) | 6 (2.0)
Female
Liver | 15 | 15 | 15 | 15
Hepatocyte, Vacuolization Cytoplasmic | 6 (1.3) | 10 (2.7) | 14^**^ (3.1) | 14^**^ (3.7)
Skin | 4 | 4 | 2 | 8
Epidermis, Hyperplasia | 0 | 0 | 1 (3.0) | 4 (2.8)
Stomach, Forestomach | 15 | 15 | 15 | 15
Epithelium, Hyperkeratosis | 0 | 5^*^ (1.8) | 1 (2.0) | 1 (2.0)
Epithelium, Hyperplasia | 2 (2.0) | 5 (2.0) | 2 (2.0) | 2 (2.5)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 41-Week Drinking Water Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 41-week survival probabilities for male and female mice are shown in Table 17. Survival of exposed males and females was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, and Clinical Findings

Mean body weights of 500, 1,000, and 2,000 mg/L males and females were generally less than those of the controls after weeks 35, 8, and 11 (males) and weeks 27, 28, and 26 (females), respectively (Figure 4; Tables 18 and 19). Water consumption by the 2,000 mg/L males and females was less than that by the control groups throughout the study (Tables H3 and H4). Drinking water concentrations of 500, 1,000, and 2,000 mg/L resulted in average daily doses of approximately 75, 150, and 230 mg dichloroacetic acid/kg body weight to males and 90, 185, and 265 mg/kg to females. There were no chemical-related clinical findings.

TABLE 17 Survival of Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 0 | 1 | 0 | 0
Natural deaths | 1 | 0 | 0 | 0
Animals surviving to study termination | 9 | 9 | 10 | 10
Percent probability of survival at end of study^a^ | 90 | 90 | 100 | 100
Mean survival (days)^b^ | 262 | 268 | 281 | 281
Survival analysis^c^ | P=0.459N | P=1.000N | P=1.000N | P=1.000N
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 0 | 1 | 2
Natural deaths | 2 | 1 | 2 | 0
Animals surviving to study termination | 7 | 9 | 7 | 8
Percent probability of survival at end of study | 70 | 90 | 70 | 80
Mean survival (days) | 233 | 274 | 237 | 245
Survival analysis | P=1.000N | P=0.500N | P=1.000N | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

FIGURE 4 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Dichloroacetic Acid in Drinking Water for 41 Weeks

TABLE 18 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.1 | 10 | 21.6 | 98 | 10 | 21.5 | 97 | 10 | 21.7 | 98 | 10
2 | 22.7 | 10 | 22.3 | 98 | 10 | 22.8 | 100 | 10 | 23.0 | 101 | 10
3 | 24.4 | 10 | 24.8 | 102 | 10 | 23.8 | 98 | 10 | 24.6 | 101 | 10
4 | 25.2 | 10 | 25.9 | 103 | 10 | 25.3 | 100 | 10 | 25.7 | 102 | 10
5 | 27.5 | 10 | 26.6 | 97 | 10 | 26.2 | 95 | 10 | 26.6 | 97 | 10
6 | 28.7 | 10 | 27.8 | 97 | 10 | 27.3 | 95 | 10 | 27.7 | 97 | 10
7 | 28.6 | 10 | 27.3 | 96 | 10 | 26.9 | 94 | 10 | 28.1 | 98 | 10
8 | 29.3 | 10 | 28.6 | 98 | 10 | 28.0 | 96 | 10 | 29.1 | 99 | 10
9 | 30.3 | 10 | 29.0 | 96 | 10 | 28.2 | 93 | 10 | 29.6 | 98 | 10
10 | 31.2 | 10 | 29.2 | 94 | 10 | 28.8 | 92 | 10 | 29.3 | 94 | 10
11 | 31.6 | 10 | 30.5 | 97 | 10 | 29.4 | 93 | 10 | 29.9 | 95 | 10
12 | 32.5 | 10 | 29.9 | 92 | 10 | 29.4 | 91 | 10 | 30.1 | 93 | 10
13 | 32.7 | 10 | 31.0 | 95 | 10 | 30.3 | 93 | 10 | 30.7 | 94 | 10
14 | 33.7 | 9 | 31.7 | 94 | 10 | 30.7 | 91 | 10 | 30.8 | 91 | 10
15 | 33.9 | 9 | 31.9 | 94 | 10 | 30.9 | 91 | 10 | 31.4 | 93 | 10
16 | 34.4 | 9 | 32.6 | 95 | 10 | 31.2 | 91 | 10 | 31.6 | 92 | 10
17 | 35.2 | 9 | 33.5 | 95 | 10 | 31.9 | 91 | 10 | 32.8 | 93 | 10
18 | 35.6 | 9 | 33.7 | 95 | 10 | 32.1 | 90 | 10 | 32.3 | 91 | 10
19 | 36.4 | 9 | 34.1 | 94 | 10 | 32.8 | 90 | 10 | 32.8 | 90 | 10
20 | 36.8 | 9 | 34.2 | 93 | 10 | 33.3 | 91 | 10 | 33.1 | 90 | 10
21 | 37.5 | 9 | 34.0 | 91 | 10 | 33.7 | 90 | 10 | 34.1 | 91 | 10
22 | 37.7 | 9 | 34.2 | 91 | 10 | 34.2 | 91 | 10 | 34.4 | 91 | 10
23 | 37.4 | 9 | 36.3 | 97 | 9 | 34.3 | 92 | 10 | 34.2 | 91 | 10
24 | 37.9 | 9 | 35.9 | 95 | 9 | 35.1 | 93 | 10 | 34.9 | 92 | 10
25 | 38.0 | 9 | 37.1 | 98 | 9 | 35.2 | 93 | 10 | 35.7 | 94 | 10
26 | 38.5 | 9 | 36.6 | 95 | 9 | 35.0 | 91 | 10 | 35.8 | 93 | 10
27 | 38.4 | 9 | 38.2 | 100 | 9 | 35.2 | 92 | 10 | 35.7 | 93 | 10
28 | 39.0 | 9 | 37.4 | 96 | 9 | 35.6 | 91 | 10 | 35.8 | 92 | 10
29 | 38.2 | 9 | 36.9 | 97 | 9 | 34.9 | 91 | 10 | 34.9 | 91 | 10
30 | 38.7 | 9 | 37.4 | 97 | 9 | 35.4 | 92 | 10 | 35.6 | 92 | 10
31 | 39.0 | 9 | 37.6 | 96 | 9 | 36.0 | 92 | 10 | 35.7 | 92 | 10
32 | 39.2 | 9 | 38.4 | 98 | 9 | 36.6 | 93 | 10 | 36.1 | 92 | 10
33 | 39.9 | 9 | 39.0 | 98 | 9 | 37.0 | 93 | 10 | 36.1 | 91 | 10
34 | 39.5 | 9 | 38.1 | 97 | 9 | 36.8 | 93 | 10 | 35.6 | 90 | 10
35 | 40.2 | 9 | 38.7 | 96 | 9 | 36.2 | 90 | 10 | 35.2 | 88 | 10
36 | 40.4 | 9 | 37.2 | 92 | 9 | 36.4 | 90 | 10 | 34.8 | 86 | 10
37 | 40.1 | 9 | 37.1 | 93 | 9 | 36.0 | 90 | 10 | 34.7 | 87 | 10
38 | 40.8 | 9 | 35.8 | 88 | 9 | 36.4 | 89 | 10 | 35.0 | 86 | 10
39 | 39.6 | 9 | 37.3 | 94 | 9 | 36.4 | 92 | 10 | 35.0 | 88 | 10
40 | 39.2 | 9 | 37.4 | 95 | 9 | 36.4 | 93 | 10 | 34.4 | 88 | 10
Mean for weeks
1–13 | 28.2 | | 27.3 | 97 | | 26.8 | 95 | | 27.4 | 97
14–40 | 38.0 | | 36.0 | 95 | | 34.7 | 91 | | 34.4 | 91

TABLE 19 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.2 | 10 | 18.9 | 98 | 10 | 19.0 | 99 | 10 | 19.1 | 100 | 10
2 | 19.0 | 10 | 18.5 | 97 | 10 | 19.0 | 100 | 10 | 19.3 | 102 | 10
3 | 20.2 | 10 | 20.2 | 100 | 10 | 20.3 | 101 | 10 | 20.5 | 102 | 10
4 | 21.6 | 10 | 21.0 | 97 | 10 | 21.3 | 99 | 10 | 21.3 | 99 | 10
5 | 22.3 | 10 | 22.2 | 100 | 10 | 22.1 | 99 | 10 | 22.2 | 100 | 10
6 | 23.1 | 10 | 23.1 | 100 | 10 | 23.0 | 100 | 10 | 22.7 | 98 | 10
7 | 23.3 | 10 | 23.1 | 99 | 10 | 23.3 | 100 | 10 | 22.8 | 98 | 10
8 | 23.8 | 10 | 23.9 | 100 | 10 | 24.2 | 102 | 10 | 23.2 | 98 | 10
9 | 24.0 | 10 | 24.1 | 100 | 10 | 24.2 | 101 | 10 | 23.7 | 99 | 10
10 | 24.0 | 10 | 23.8 | 99 | 10 | 24.3 | 101 | 10 | 23.2 | 97 | 10
11 | 25.1 | 10 | 24.9 | 99 | 10 | 24.5 | 98 | 10 | 24.5 | 98 | 10
12 | 24.9 | 10 | 24.3 | 98 | 10 | 25.0 | 100 | 9 | 24.8 | 100 | 10
13 | 26.2 | 10 | 25.3 | 97 | 10 | 25.1 | 96 | 9 | 25.4 | 97 | 10
14 | 27.3 | 10 | 25.5 | 93 | 10 | 25.6 | 94 | 9 | 25.0 | 92 | 9
15 | 26.0 | 9 | 24.5 | 94 | 10 | 25.5 | 98 | 9 | 24.8 | 95 | 9
16 | 26.7 | 9 | 25.0 | 94 | 10 | 26.0 | 97 | 9 | 25.5 | 96 | 9
17 | 27.3 | 9 | 25.7 | 94 | 10 | 26.4 | 97 | 9 | 26.0 | 95 | 8
18 | 26.7 | 8 | 26.2 | 98 | 10 | 26.1 | 98 | 9 | 26.5 | 99 | 8
19 | 27.5 | 8 | 26.9 | 98 | 10 | 27.3 | 99 | 9 | 26.6 | 97 | 8
20 | 28.4 | 8 | 27.6 | 97 | 10 | 27.7 | 98 | 9 | 27.2 | 96 | 8
21 | 28.1 | 8 | 27.2 | 97 | 10 | 27.5 | 98 | 8 | 26.9 | 96 | 8
22 | 28.6 | 7 | 27.6 | 97 | 10 | 27.7 | 97 | 8 | 27.6 | 97 | 8
23 | 29.2 | 7 | 27.7 | 95 | 10 | 28.4 | 97 | 8 | 27.9 | 96 | 8
24 | 28.4 | 7 | 28.2 | 99 | 10 | 28.4 | 100 | 8 | 28.3 | 100 | 8
25 | 29.8 | 7 | 28.4 | 95 | 10 | 28.6 | 96 | 8 | 28.5 | 96 | 8
26 | 30.2 | 7 | 28.1 | 93 | 10 | 27.9 | 92 | 8 | 28.9 | 96 | 8
27 | 31.3 | 7 | 29.6 | 95 | 10 | 30.0 | 96 | 7 | 28.9 | 92 | 8
28 | 31.5 | 7 | 29.6 | 94 | 10 | 30.2 | 96 | 7 | 29.6 | 94 | 8
29 | 31.9 | 7 | 28.5 | 89 | 10 | 29.9 | 94 | 7 | 29.7 | 93 | 8
30 | 32.8 | 7 | 30.3 | 92 | 9 | 30.1 | 92 | 7 | 30.0 | 92 | 8
31 | 34.0 | 7 | 31.0 | 91 | 9 | 29.9 | 88 | 7 | 30.2 | 89 | 8
32 | 33.6 | 7 | 31.0 | 92 | 9 | 31.0 | 92 | 7 | 30.3 | 90 | 8
33 | 33.3 | 7 | 31.7 | 95 | 9 | 30.9 | 93 | 7 | 30.1 | 90 | 8
34 | 34.9 | 7 | 32.2 | 92 | 9 | 31.5 | 90 | 7 | 30.2 | 87 | 8
35 | 35.7 | 7 | 32.0 | 90 | 9 | 30.8 | 86 | 7 | 30.2 | 85 | 8
36 | 36.1 | 7 | 32.1 | 89 | 9 | 30.4 | 84 | 7 | 29.7 | 82 | 8
37 | 35.4 | 7 | 32.1 | 91 | 9 | 30.0 | 85 | 7 | 27.6 | 78 | 8
38 | 36.3 | 7 | 33.2 | 92 | 9 | 29.1 | 80 | 7 | 28.7 | 79 | 8
39 | 35.1 | 7 | 33.8 | 96 | 9 | 30.3 | 86 | 7 | 28.1 | 80 | 8
40 | 34.9 | 7 | 33.6 | 96 | 9 | 30.1 | 86 | 7 | 27.9 | 80 | 8
Mean for weeks
1–13 | 22.8 | | 22.6 | 99 | | 22.7 | 100 | | 22.5 | 99
14–40 | 31.1 | | 29.2 | 94 | | 28.8 | 93 | | 28.2 | 91

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the forestomach, lung, liver, ovary, and thyroid gland. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables B5 through B8.

Forestomach: The incidence of multiple squamous cell papillomas in the 500 mg/L females was significantly increased compared to the controls (Tables 20 and B7). Papillomas were morphologically similar to that previously described in the 26-week dermal study.

Lung: The incidence of alveolar/bronchiolar adenoma in the 1,000 mg/L males was significantly increased compared to the controls (Tables 20 and B5). Two female mice exposed to 2,000 mg/L also had alveolar/bronchiolar adenomas of the lung (Tables 20 and B7)

Liver: The incidences of hepatocyte cytoplasmic vacuolization in all exposed groups were similar to those in the controls; however, there was an exposure-related increase in the mean severity (Tables 20, B6, and B8). Hepatocyte cytoplasmic vacuolization was morphologically similar to that previously described in the 26-week dermal study.

Ovary: The incidences of ovarian cysts were significantly increased in the 500 and 1,000 mg/L females compared to the controls (Tables 20 and B8).

Thyroid gland: The incidence of follicle degeneration in 500 mg/L males was significantly increased (Tables 20 and B6). Because the incidences in exposed females were not significantly increased (Table B8) and the incidences were not related to exposure concentration, the increase in the 500 mg/L males was not considered related to exposure.

TABLE 20 Incidences of Selected Neoplasms and Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Lung^a,b^ | 10 | 10 | 10 | 10
Alveolar/bronchiolar Adenoma (includes multiple)^c^ | 1 | 2 | 7^**^ | 3
Liver | 10 | 10 | 10 | 10
Hepatocyte, Vacuolization Cytoplasmic | 9 (2.0)^d^ | 10 (2.3) | 9 (3.2) | 10 (3.8)
Thyroid Gland | 10 | 10 | 10 | 10
Follicle, Degeneration | 3 (1.0) | 9^**^ (1.1) | 5 (1.2) | 4 (1.0)
Female
Lung | 10 | 10 | 10 | 10
Alveolar/bronchiolar Adenoma | 0 | 0 | 0 | 2
Stomach, Forestomach | 10 | 10 | 10 | 10
Squamous Cell Papilloma, Multiple | 1 | 6^*^ | 4 | 4
Squamous Cell Papilloma (includes multiple) | 6 | 7 | 7 | 6
Liver | 10 | 10 | 10 | 10
Hepatocyte, Vacuolization Cytoplasmic | 7 (2.0) | 9 (2.6) | 9 (2.9) | 10 (3.0)
Ovary | 10 | 10 | 10 | 10
Cyst | 0 | 7^**^ (2.0) | 4^*^ (2.0) | 1 (2.0)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Pulmonary neoplasms are not common in unexposed male Tg.AC hemizygous mice. In ten studies (including this study) for dermal, drinking water, and gavage routes of exposure, no pulmonary carcinomas were found at 39 to 43 weeks, and pulmonary adenomas were found in 4 of 112 (3.6%) Tg.AC hemizygous control mice.

c Number of animals with lesion

d Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 26-Week Drinking Water Study in p53 Haploinsufficient Mice

### Survival

Estimates of 26-week survival probabilities for male and female mice are shown in Table 21. Survival of all exposed groups was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, and Clinical Findings

The mean body weights of the 1,000 and 2,000 mg/L males after weeks 4 and 2, respectively, and those of 1,000 and 2,000 mg/L females after weeks 11 and 10, respectively, were less than those of the control groups (Figure 5; Tables 22 and 23). Water consumption by 1,000 and 2,000 mg/L males and females was less than that by the control groups throughout the study (Tables H5 and H6). Drinking water concentrations of 500, 1,000, and 2,000 mg/L resulted in average daily doses of approximately 45, 80, and 150 mg/kg to males and 80, 145, and 220 mg/kg to females. No clinical findings were reported for male or female p53 haploinsufficient mice in the 26-week study.

### Hematology

Hematology data are shown in Table E3. While minimal changes, some of which reached statistical significance, were seen, none were considered to be biologically relevant or related to dichloroacetic acid exposure.

TABLE 21 Survival of p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Animals initially in study | 15 | 15 | 15 | 15
Animals surviving to study termination | 15 | 15 | 15 | 15
Percent probability of survival at end of study^a^ | 100 | 100 | 100 | 100
Mean survival (days)^b^ | 177 | 177 | 177 | 177
Survival analysis^c^ | —^d^ | — | — | —
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 0 | 1
Natural deaths | 0 | 0 | 1 | 0
Animals surviving to study termination | 15 | 15 | 14 | 14
Percent probability of survival at end of study | 100 | 100 | 93 | 93
Mean survival (days) | 178 | 178 | 177 | 177
Survival analysis | P=0.469 | — | P=1.000 | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns.

d Value of statistic cannot be computed.

FIGURE 5 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Dichloroacetic Acid in Drinking Water for 26 Weeks

TABLE 22 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.1 | 15 | 23.1 | 100 | 15 | 22.7 | 98 | 15 | 22.9 | 99 | 15
2 | 24.1 | 15 | 24.0 | 100 | 15 | 23.7 | 98 | 15 | 22.8 | 95 | 15
3 | 25.1 | 15 | 24.8 | 99 | 15 | 23.8 | 95 | 15 | 23.6 | 94 | 15
4 | 26.4 | 15 | 26.2 | 99 | 15 | 25.4 | 96 | 15 | 24.3 | 92 | 15
5 | 27.8 | 15 | 27.6 | 99 | 15 | 26.1 | 94 | 15 | 25.1 | 90 | 15
6 | 28.9 | 15 | 28.5 | 99 | 15 | 26.6 | 92 | 15 | 25.5 | 88 | 15
7 | 30.7 | 15 | 29.8 | 97 | 15 | 27.9 | 91 | 15 | 25.9 | 84 | 15
8 | 31.9 | 15 | 30.7 | 96 | 15 | 28.6 | 90 | 15 | 26.5 | 83 | 15
9 | 33.3 | 15 | 31.7 | 95 | 15 | 29.2 | 88 | 15 | 27.1 | 81 | 15
10 | 34.7 | 15 | 33.2 | 96 | 15 | 29.8 | 86 | 15 | 27.4 | 79 | 15
11 | 36.2 | 15 | 34.0 | 94 | 15 | 30.5 | 84 | 15 | 27.9 | 77 | 15
12 | 37.4 | 15 | 35.2 | 94 | 15 | 31.1 | 83 | 15 | 28.4 | 76 | 15
13 | 38.6 | 15 | 36.2 | 94 | 15 | 31.1 | 81 | 15 | 28.6 | 74 | 15
14 | 39.5 | 15 | 37.1 | 94 | 15 | 31.5 | 80 | 15 | 29.2 | 74 | 15
15 | 40.9 | 15 | 38.4 | 94 | 15 | 32.5 | 80 | 15 | 29.4 | 72 | 15
16 | 41.4 | 15 | 38.6 | 93 | 15 | 32.4 | 78 | 15 | 29.5 | 71 | 15
17 | 42.1 | 15 | 39.8 | 95 | 15 | 33.1 | 79 | 15 | 29.4 | 70 | 15
18 | 43.4 | 15 | 40.6 | 94 | 15 | 33.8 | 78 | 15 | 30.5 | 70 | 15
19 | 44.6 | 15 | 41.7 | 94 | 15 | 34.6 | 78 | 15 | 31.1 | 70 | 15
20 | 44.9 | 15 | 42.2 | 94 | 15 | 35.0 | 78 | 15 | 31.5 | 70 | 15
21 | 45.5 | 15 | 43.2 | 95 | 15 | 35.6 | 78 | 15 | 31.8 | 70 | 15
22 | 45.8 | 15 | 43.5 | 95 | 15 | 35.8 | 78 | 15 | 32.2 | 70 | 15
23 | 46.2 | 15 | 44.0 | 95 | 15 | 36.1 | 78 | 15 | 32.4 | 70 | 15
24 | 46.7 | 15 | 44.4 | 95 | 15 | 36.8 | 79 | 15 | 33.1 | 71 | 15
25 | 46.9 | 15 | 44.6 | 95 | 15 | 36.6 | 78 | 15 | 32.3 | 69 | 15
Mean for weeks
1–13 | 30.6 | | 29.6 | 97 | | 27.4 | 90 | | 25.8 | 84
14–25 | 44.0 | | 41.5 | 94 | | 34.5 | 78 | | 31.0 | 70

TABLE 23 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.7 | 15 | 18.6 | 100 | 15 | 18.8 | 101 | 15 | 18.4 | 98 | 15
2 | 19.5 | 15 | 19.6 | 101 | 15 | 19.5 | 100 | 15 | 18.5 | 95 | 15
3 | 19.9 | 15 | 20.1 | 101 | 15 | 19.7 | 99 | 15 | 18.7 | 94 | 15
4 | 20.9 | 15 | 20.6 | 99 | 15 | 20.3 | 97 | 15 | 19.6 | 94 | 15
5 | 21.5 | 15 | 21.3 | 99 | 15 | 20.9 | 97 | 15 | 20.3 | 94 | 15
6 | 21.7 | 15 | 21.4 | 99 | 15 | 20.9 | 96 | 15 | 20.7 | 95 | 15
7 | 21.9 | 15 | 21.7 | 99 | 15 | 21.5 | 98 | 15 | 21.3 | 97 | 15
8 | 23.0 | 15 | 22.6 | 98 | 15 | 22.3 | 97 | 15 | 22.0 | 96 | 15
9 | 23.3 | 15 | 22.9 | 98 | 15 | 21.3 | 91 | 15 | 21.8 | 94 | 15
10 | 23.2 | 15 | 22.3 | 96 | 15 | 22.2 | 96 | 15 | 22.4 | 97 | 15
11 | 23.7 | 15 | 23.1 | 98 | 15 | 22.5 | 95 | 15 | 22.2 | 94 | 15
12 | 24.5 | 15 | 23.9 | 98 | 15 | 22.9 | 94 | 15 | 22.8 | 93 | 15
13 | 24.3 | 15 | 23.9 | 98 | 15 | 22.8 | 94 | 15 | 22.7 | 93 | 15
14 | 24.7 | 15 | 24.5 | 99 | 15 | 23.3 | 94 | 15 | 22.8 | 92 | 15
15 | 25.3 | 15 | 24.7 | 98 | 15 | 23.6 | 93 | 15 | 23.4 | 93 | 15
16 | 25.5 | 15 | 24.6 | 97 | 15 | 23.7 | 93 | 15 | 23.4 | 92 | 15
17 | 24.6 | 15 | 24.8 | 101 | 15 | 23.2 | 94 | 15 | 22.6 | 92 | 15
18 | 26.8 | 15 | 25.3 | 94 | 15 | 24.1 | 90 | 15 | 23.7 | 88 | 15
19 | 27.0 | 15 | 26.3 | 97 | 15 | 24.3 | 90 | 15 | 23.8 | 88 | 15
20 | 27.4 | 15 | 26.4 | 96 | 15 | 24.3 | 89 | 15 | 24.3 | 89 | 15
21 | 28.1 | 15 | 27.5 | 98 | 15 | 24.6 | 88 | 15 | 24.5 | 87 | 15
22 | 28.1 | 15 | 27.3 | 97 | 15 | 24.6 | 88 | 15 | 24.4 | 87 | 15
23 | 29.1 | 15 | 27.6 | 95 | 15 | 24.5 | 84 | 15 | 24.4 | 84 | 15
24 | 29.2 | 15 | 27.9 | 96 | 15 | 24.6 | 84 | 15 | 24.7 | 85 | 15
25 | 30.0 | 15 | 28.5 | 95 | 15 | 24.9 | 83 | 14 | 24.7 | 82 | 14
Mean for weeks
1–13 | 22.0 | | 21.7 | 99 | | 21.2 | 96 | | 20.9 | 95
14–25 | 27.2 | | 26.3 | 97 | | 24.1 | 89 | | 23.9 | 88

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver, pituitary gland, and thymus. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables C1 through C4.

Liver: The incidences of hepatocyte cytoplasmic vacuolization were significantly increased in all exposed groups of females (Tables 24 and C4). In both sexes, the average severity of cytoplasmic vacuolization generally increased with increasing exposure concentration.

Although morphologically similar to lesions in the Tg.AC dermal and drinking water studies, the hepatocyte cytoplasmic vacuolization in the p53 haploinsufficient mice was generally more pronounced.

Pituitary gland: The incidence of pars distalis hyperplasia was significantly increased in the 1,000 mg/L males compared to the controls (Tables 24 and C2).

Thymus: The incidence of thymocyte necrosis was significantly increased in females exposed to 500 mg/L compared to the controls (Tables 24 and C4).

TABLE 24 Incidences of Selected Nonneoplastic Lesions in p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Liver^a^ | 15 | 15 | 15 | 15
Hepatocyte, Vacuolization Cytoplasmic^b^ | 15 (2.7)^c^ | 15 (3.4) | 15 (3.4) | 15 (4.0)
Pituitary Gland | 15 | 15 | 15 | 15
Pars Distalis, Hyperplasia | 0 | 0 | 6^**^ (1.0) | 0
Female
Liver | 15 | 15 | 15 | 15
Hepatocyte, Vacuolization Cytoplasmic | 3 (1.0) | 15^**^ (2.2) | 15^**^ (3.1) | 15^**^ (3.5)
Thymus | 15 | 15 | 15 | 15
Thymocyte, Necrosis | 0 | 6^**^ (1.8) | 2 (2.0) | 1 (2.0)

** Significantly different (P≤0.01) from the control group by the Fisher exact test

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 41-Week Drinking Water Study in p53 Haploinsufficient Mice

### Survival

Estimates of 41-week survival probabilities for male and female mice are shown in Table 25. Survival of all exposed groups was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, and Clinical Findings

The mean body weights of exposed groups of males were less than those of the controls after 4 (500 mg/L), 3 (1,000 mg/L), and 1 (2,000 mg/L) weeks on the study (Table 26 and Figure 6). The mean body weights of 1,000 and 2,000 mg/L females were less after week 9, and those of 500 mg/L females were less after week 27 (Table 27 and Figure 6). Water consumption by males and females exposed to 1,000 or 2,000 mg/L was less than that by the controls throughout the study (Tables H7 and H8). Drinking water concentrations of 500, 1,000, and 2,000 mg/L resulted in average daily doses of approximately 45, 80, and 140 mg/kg to males and 65, 140, and 220 mg/kg to females. No chemical-related clinical findings were observed.

TABLE 25 Survival of p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Animals initially in study | 10 | 10 | 10 | 10
Natural deaths | 1 | 0 | 1 | 0
Animals surviving to study termination | 9 | 10 | 9 | 10
Percent probability of survival at end of study^a^ | 90 | 100 | 90 | 100
Mean survival (days)^b^ | 273 | 282 | 280 | 282
Survival analysis^c^ | P=0.794N | P=1.000N | P=1.000N | P=1.000N
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 0 | 1 | 0 | 0
Natural deaths | 0 | 0 | 0 | 1
Animals surviving to study termination | 10 | 9 | 10 | 9
Percent probability of survival at end of study | 100 | 90 | 100 | 90
Mean survival (days) | 283 | 282 | 283 | 275
Survival analysis | P=0.788 | P=1.000 | —^d^ | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

d Value of statistic cannot be computed.

TABLE 26 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.5 | 10 | 22.7 | 97 | 10 | 23.3 | 99 | 10 | 23.2 | 99 | 10
2 | 24.4 | 10 | 23.7 | 97 | 10 | 23.7 | 97 | 10 | 22.8 | 93 | 10
3 | 24.9 | 10 | 24.6 | 99 | 10 | 24.0 | 96 | 10 | 23.5 | 94 | 10
4 | 27.1 | 10 | 25.6 | 95 | 10 | 25.2 | 93 | 10 | 24.6 | 91 | 10
5 | 28.2 | 10 | 26.6 | 94 | 10 | 25.9 | 92 | 10 | 25.4 | 90 | 10
6 | 29.4 | 10 | 27.6 | 94 | 10 | 26.4 | 90 | 10 | 26.0 | 88 | 10
7 | 30.9 | 10 | 27.9 | 90 | 10 | 27.1 | 88 | 10 | 26.6 | 86 | 10
8 | 32.5 | 10 | 29.6 | 91 | 10 | 27.6 | 85 | 10 | 27.3 | 84 | 10
9 | 34.0 | 10 | 30.4 | 89 | 10 | 27.8 | 82 | 10 | 27.5 | 81 | 10
10 | 34.3 | 10 | 31.6 | 92 | 10 | 28.2 | 82 | 10 | 28.0 | 82 | 10
11 | 36.3 | 10 | 31.9 | 88 | 10 | 28.7 | 79 | 10 | 28.0 | 77 | 10
12 | 37.2 | 10 | 33.2 | 89 | 10 | 29.4 | 79 | 10 | 28.8 | 77 | 10
13 | 38.6 | 10 | 34.4 | 89 | 10 | 29.8 | 77 | 10 | 29.2 | 76 | 10
14 | 39.7 | 10 | 35.5 | 89 | 10 | 30.4 | 77 | 10 | 30.0 | 76 | 10
15 | 40.9 | 10 | 35.8 | 88 | 10 | 30.6 | 75 | 10 | 30.4 | 74 | 10
16 | 41.8 | 10 | 36.9 | 88 | 10 | 30.5 | 73 | 10 | 30.9 | 74 | 10
17 | 42.4 | 10 | 37.4 | 88 | 10 | 30.6 | 72 | 10 | 29.7 | 70 | 10
18 | 43.4 | 10 | 38.0 | 88 | 10 | 31.0 | 71 | 10 | 31.5 | 73 | 10
19 | 44.0 | 10 | 38.8 | 88 | 10 | 31.3 | 71 | 10 | 32.0 | 73 | 10
20 | 45.0 | 10 | 39.7 | 88 | 10 | 31.9 | 71 | 10 | 32.4 | 72 | 10
21 | 45.5 | 10 | 40.2 | 88 | 10 | 32.5 | 71 | 10 | 32.4 | 71 | 10
22 | 45.9 | 10 | 40.5 | 88 | 10 | 32.8 | 72 | 10 | 32.9 | 72 | 10
23 | 46.8 | 10 | 41.6 | 89 | 10 | 33.6 | 72 | 10 | 33.7 | 72 | 10
24 | 47.3 | 10 | 42.2 | 89 | 10 | 34.5 | 73 | 10 | 34.2 | 72 | 10
25 | 47.3 | 10 | 42.1 | 89 | 10 | 33.8 | 72 | 10 | 33.8 | 72 | 10
26 | 47.4 | 10 | 42.5 | 90 | 10 | 33.6 | 71 | 10 | 33.4 | 71 | 10
27 | 47.7 | 10 | 42.6 | 89 | 10 | 33.8 | 71 | 10 | 33.4 | 70 | 10
28 | 48.3 | 9 | 42.7 | 88 | 10 | 33.8 | 70 | 10 | 33.4 | 69 | 10
29 | 48.4 | 9 | 42.8 | 88 | 10 | 33.6 | 69 | 10 | 33.2 | 69 | 10
30 | 49.1 | 9 | 43.8 | 89 | 10 | 34.3 | 70 | 10 | 34.1 | 70 | 10
31 | 49.5 | 9 | 44.1 | 89 | 10 | 34.4 | 70 | 10 | 34.4 | 70 | 10
32 | 50.0 | 9 | 45.1 | 90 | 10 | 35.3 | 71 | 10 | 34.8 | 70 | 10
33 | 50.6 | 9 | 45.4 | 90 | 10 | 35.5 | 70 | 10 | 34.8 | 69 | 10
34 | 50.5 | 9 | 45.9 | 91 | 10 | 35.0 | 69 | 10 | 34.0 | 67 | 10
35 | 50.3 | 9 | 46.1 | 92 | 10 | 34.0 | 68 | 10 | 33.5 | 67 | 10
36 | 50.9 | 9 | 46.2 | 91 | 10 | 34.3 | 67 | 10 | 33.7 | 66 | 10
37 | 50.8 | 9 | 45.5 | 90 | 10 | 33.2 | 65 | 10 | 33.3 | 66 | 10
38 | 51.1 | 9 | 44.7 | 88 | 10 | 32.9 | 64 | 10 | 34.1 | 67 | 10
39 | 50.0 | 9 | 45.6 | 91 | 10 | 34.2 | 68 | 9 | 34.1 | 68 | 10
40 | 51.0 | 9 | 45.9 | 90 | 10 | 33.8 | 66 | 9 | 35.0 | 69 | 10
Mean for weeks
1–13 | 30.9 | | 28.4 | 92 | | 26.7 | 86 | | 26.2 | 85
14–40 | 47.2 | | 42.1 | 89 | | 33.2 | 70 | | 33.1 | 70

TABLE 27 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Weeks on Study | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.6 | 10 | 18.6 | 100 | 10 | 18.7 | 101 | 10 | 18.9 | 102 | 10
2 | 19.5 | 10 | 19.1 | 98 | 10 | 19.1 | 98 | 10 | 18.5 | 95 | 10
3 | 20.1 | 10 | 19.6 | 98 | 10 | 19.7 | 98 | 10 | 19.3 | 96 | 10
4 | 21.2 | 10 | 21.1 | 100 | 10 | 20.2 | 95 | 10 | 19.9 | 94 | 10
5 | 21.9 | 10 | 22.1 | 101 | 10 | 20.8 | 95 | 10 | 20.7 | 95 | 10
6 | 22.1 | 10 | 22.4 | 101 | 10 | 20.9 | 95 | 10 | 21.0 | 95 | 10
7 | 22.3 | 10 | 22.6 | 101 | 10 | 20.7 | 93 | 10 | 21.1 | 95 | 10
8 | 23.2 | 10 | 23.4 | 101 | 10 | 21.6 | 93 | 10 | 21.5 | 93 | 10
9 | 23.8 | 10 | 23.6 | 99 | 10 | 21.7 | 91 | 10 | 21.8 | 92 | 10
10 | 23.0 | 10 | 24.1 | 105 | 10 | 21.9 | 95 | 10 | 22.0 | 96 | 10
11 | 24.6 | 10 | 24.6 | 100 | 10 | 22.1 | 90 | 10 | 22.3 | 91 | 10
12 | 24.9 | 10 | 25.4 | 102 | 10 | 22.5 | 90 | 10 | 22.7 | 91 | 10
13 | 25.4 | 10 | 26.0 | 102 | 10 | 22.9 | 90 | 10 | 22.8 | 90 | 10
14 | 26.4 | 10 | 26.7 | 101 | 10 | 23.0 | 87 | 10 | 23.6 | 89 | 10
15 | 27.4 | 10 | 26.8 | 98 | 10 | 23.2 | 85 | 10 | 23.4 | 85 | 10
16 | 27.6 | 10 | 27.5 | 100 | 10 | 23.2 | 84 | 10 | 23.7 | 86 | 10
17 | 27.1 | 10 | 27.0 | 100 | 10 | 22.7 | 84 | 10 | 23.0 | 85 | 10
18 | 28.3 | 10 | 27.5 | 97 | 10 | 23.7 | 84 | 10 | 23.6 | 83 | 10
19 | 29.2 | 10 | 27.8 | 95 | 10 | 24.0 | 82 | 10 | 23.9 | 82 | 10
20 | 28.8 | 10 | 28.5 | 99 | 10 | 23.8 | 83 | 10 | 24.0 | 83 | 10
21 | 30.3 | 10 | 29.4 | 97 | 10 | 24.6 | 81 | 10 | 24.5 | 81 | 10
22 | 30.8 | 10 | 29.8 | 97 | 10 | 24.6 | 80 | 10 | 24.6 | 80 | 10
23 | 31.6 | 10 | 30.6 | 97 | 10 | 25.1 | 79 | 10 | 24.9 | 79 | 10
24 | 32.3 | 10 | 31.1 | 96 | 10 | 25.3 | 78 | 10 | 25.1 | 78 | 10
25 | 32.8 | 10 | 31.3 | 95 | 10 | 25.1 | 77 | 10 | 24.7 | 75 | 10
26 | 33.2 | 10 | 30.8 | 93 | 10 | 25.3 | 76 | 10 | 24.6 | 74 | 10
27 | 33.4 | 10 | 31.7 | 95 | 10 | 25.3 | 76 | 10 | 24.5 | 73 | 10
28 | 34.1 | 10 | 31.9 | 94 | 10 | 25.3 | 74 | 10 | 24.6 | 72 | 10
29 | 34.9 | 10 | 32.9 | 94 | 10 | 25.1 | 72 | 10 | 25.3 | 73 | 10
30 | 36.8 | 10 | 33.8 | 92 | 10 | 25.9 | 70 | 10 | 25.7 | 70 | 9
31 | 37.6 | 10 | 33.7 | 90 | 10 | 25.9 | 69 | 10 | 25.3 | 67 | 9
32 | 38.5 | 10 | 34.7 | 90 | 10 | 26.3 | 68 | 10 | 25.6 | 67 | 9
33 | 38.7 | 10 | 34.6 | 89 | 10 | 26.3 | 68 | 10 | 25.6 | 66 | 9
34 | 39.8 | 10 | 35.6 | 89 | 10 | 26.2 | 66 | 10 | 25.3 | 64 | 9
35 | 40.1 | 10 | 36.0 | 90 | 10 | 25.9 | 65 | 10 | 25.4 | 63 | 9
36 | 40.4 | 10 | 36.8 | 91 | 10 | 26.2 | 65 | 10 | 25.1 | 62 | 9
37 | 40.7 | 10 | 35.9 | 88 | 10 | 26.4 | 65 | 10 | 25.5 | 63 | 9
38 | 41.3 | 10 | 35.4 | 86 | 10 | 26.8 | 65 | 10 | 25.9 | 63 | 9
39 | 42.5 | 10 | 35.8 | 84 | 10 | 26.0 | 61 | 10 | 25.3 | 60 | 9
40 | 43.3 | 10 | 37.7 | 87 | 9 | 27.1 | 63 | 10 | 26.1 | 60 | 9
Mean for weeks
1–13 | 22.4 | | 22.5 | 100 | | 21.0 | 94 | | 21.0 | 94
14–40 | 34.4 | | 31.9 | 93 | | 25.1 | 73 | | 24.8 | 72

FIGURE 6 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Dichloroacetic Acid in Drinking Water for 41 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the liver and ovary. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables C5 through C8.

Liver: The incidences of hepatocyte cytoplasmic vacuolization in exposed groups were similar to those in the controls; however, the average severity generally increased with increasing exposure concentration in females (Tables 28, C6, and C8). Hepatocellular adenoma was also observed in two 500 mg/L males (Tables 28 and C5). Hepatocyte cytoplasmic vacuolization was morphologically similar to that in the 26-week drinking water study in p53 haploinsufficient mice.

Ovary: The incidence of ovarian cyst in 2,000 mg/L females was significantly increased compared to the control group (Tables 28 and C8).

TABLE 28 Incidences of Selected Neoplasms and Nonneoplastic Lesions in p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Liver^a^ | 10 | 10 | 10 | 10
Hepatocyte, Vacuolization Cytoplasmic^b^ | 9 (3.6)^c^ | 10 (3.0) | 10 (3.7) | 10 (3.8)
Hepatocellular Adenoma | 0 | 2 | 0 | 0
Female
Liver | 10 | 10 | 10 | 10
Hepatocyte, Vacuolization Cytoplasmic | 10 (1.9) | 10 (2.7) | 10 (3.7) | 10 (3.6)
Ovary | 10 | 10 | 10 | 10
Cyst | 0 | 1 (2.0) | 1 (3.0) | 7^**^ (2.0)

** Significantly different (P≤0.01) from the control group by the Fisher exact test

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## Genetic Toxicology

Dichloroacetic acid (concentration range of 33 to 6,666 µg/plate) was mutagenic in Salmonella typhimurium strains TA100 and TA1535 in the absence of S9 liver activation enzymes; no mutation induction was observed in either of these two base-pair substitution strains when exposure occurred in the presence of 30% rat or hamster liver S9 (Table D1). Dichloroacetic acid did not induce mutations in the S. typhimurium frame-shift strain TA98, with or without S9 (Table D1).

Dichloroacetic acid was tested for micronucleus induction in peripheral blood erythrocytes of male and female Tg.AC hemizygous and p53 haploinsufficient mice treated by dermal application (31.25 to 500 mg/kg) or in drinking water (500 to 2,000 mg/L) for 26 weeks (Tables D2 through D4). No induction of micronuclei was seen in Tg.AC hemizygous mice treated by either route or in the p53 haploinsufficient mice, which were exposed only by drinking water. The percentages of polychromatic erythrocytes were not significantly altered by chemical treatment.

Peripheral blood samples from B6C3F_1_ mice exposed to dichloroacetic acid in drinking water (67 to 1,000 mg/L) were analyzed for frequency of micronucleated normochromatic erythrocytes at the end of a 3-month exposure period; no increases in micronucleated erythrocytes were seen in male mice, but a small increase was observed in females (Table D5). The increase in frequency of micronucleated erythrocytes in the female mice was judged to be equivocal due to a positive trend test (P=0.007), but none of the individual dosed groups differed significantly from the control group. The percentages of polychromatic erythrocytes were not significantly altered by chemical treatment.