# MATERIALS AND METHODS

## Procurement and Characterization

### Dichloroacetic Acid

Dichloroacetic acid was obtained from Aldrich Chemical Co. (Milwaukee, WI) in two lots (05316AR and 11905BU) that were used in the 26- and 39-week dermal studies and the 26- and 41-week drinking water studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle Memorial Institute (Columbus, OH) and by the study laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix G). Reports on analyses performed in support of the dichloroacetic acid studies are on file at the National Institute of Environmental Health Sciences.

Lots 05316AR (a yellow liquid) and 11905BU (a colorless liquid) were identified as dichloroacetic acid by infrared and nuclear magnetic resonance (NMR) (proton and carbon-13) spectroscopy. Lots 05316AR and 11905BU were identified as dichloroacetic acid by the study laboratory using infrared spectroscopy. The purity of lot 05316AR was determined by high-performance liquid chromatography (HPLC) and acid functional group titration. Moisture content of lot 11905BU was determined by Karl Fischer titration. The purity of lot 11905BU was determined using HPLC and acid functional group titration and ion chromatography (IC). Purity of the bulk chemical was monitored over the course of the study; no degradation was observed.

For lot 05316AR, HPLC indicated one major peak and three impurity peaks with areas less than 1.0% of the major peak area, a combined impurity peak area of 1.20% of the major peak area, and a purity of approximately 98.5%. HPLC indicated a purity of 99.9% relative to a frozen reference standard of the same lot. Acid functional group titration indicated a purity of approximately 99.4%. The overall purity of lot 05316AR was determined to be greater than 98.5%.

For lot 11905BU, Karl Fischer titration indicated 0.06% water. HPLC indicated one major peak and no impurity peaks greater than or equal to 0.1% of the area of the major peak and a purity of 100%. Acid functional group titration indicated a purity of approximately 100.6%. IC indicated one major peak and four impurity peaks with combined peak areas of 0.77% of the major peak area. The overall purity of lot 11905BU was determined to be greater than 99%. To ensure stability, the bulk chemical was stored at room temperature, protected from light in amber glass containers. Stability was monitored by the study laboratory during the 26-, 39-, and 41-week studies. No degradation of the bulk chemical was detected.

### 12-O-tetradecanoylphorbol-13-acetate

12-O-tetradecanoylphorbol-13-acetate (TPA) was obtained from Sigma-Aldrich Chemical Company (St. Louis, MO) in one lot (48H1178) that was used in the 26-week studies in Tg.AC hemizygous mice. Lot 48H1178, a white crystalline powder, was identified as TPA by Research Triangle Institute (RTI; Research Triangle Park, NC) using IR and proton nuclear magnetic resonance (NMR) spectrometry. All spectra were consistent with the structure of TPA.

The purity of lot 48H1178 was determined by RTI using high performance liquid chromatography. This analysis indicated one major peak and one impurity peak with an area equal to approximately 0.11% of the total integrated peak area. The overall purity of lot 48H1178 was determined to be greater than 99%. The TPA formulations were shown to be stable for at least 6 months.

### Acetone

USP-grade acetone was obtained from Spectrum Chemicals and Laboratory Products (Gardena, CA) in two lots (OG0513 and OX0312) that were used in the 26-week and 39-week dermal studies. Lots OG0513 and OX0312, clear liquids, were identified as acetone using IR spectroscopy.

The purity of lots OG0513 and OX0312 was determined using gas chromatography (GC). Analysis indicated one major peak and no impurities with areas greater than or equal to 0.1% of the major peak. The overall purity of both lots was determined to be greater than 99.9%.

## Preparation and Analysis of Dose Formulations

### Dermal Studies

The dose formulations were prepared every 1 to 5 weeks by mixing dichloroacetic acid with deionized water to obtain the required final concentration of dichloroacetic acid (Table G1). The dose formulations were stored at room temperature in amber glass bottles with Teflon^®^-lined lids and used within 35 days after formulation. TPA formulations in acetone were prepared by RTI and administered by the study laboratory.

Periodic analyses of the dose formulations of dichloroacetic acid were conducted by the study laboratory using GC. During the 26- and 39-week studies, dose formulations were analyzed five times. All 12 of the dose formulations were within 10% of the target concentrations (Table G2).

### Drinking Water Studies

Dose formulations were prepared every 1 to 5 weeks by adding a specified amount of dichloroacetic acid to tap water (Table G1). TPA formulations in acetone were prepared and stored as described for the dermal studies.

Periodic analyses of the dose formulations of dichloroacetic acid were conducted by the study laboratory using HPLC. During the 26- and 41-week studies, dose formulations were analyzed four times; all 12 of the dose formulations for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentrations (Table G3).

## Study Designs

### Dermal Studies

Groups of 15 male and 15 female Tg.AC hemizygous mice were administered 0, 31.25, 125, or 500 mg dichloroacetic acid/kg body weight in 3.3 mL water:acetone/kg body weight 5 days per week for 26 weeks. Groups of 10 male and 10 female Tg.AC hemizygous mice were administered the same doses for 39 weeks. Vehicle control mice were administered water:acetone only. Doses were applied to the clipped dorsal skin from the mid-back to the interscapular area.

### Drinking Water Studies

Groups of 15 male and 15 female Tg.AC hemizygous and p53 haploinsufficient mice were exposed to 0, 500, 1,000, or 2,000 mg dichloroacetic acid/L drinking water for 26 weeks. Groups of 10 male and 10 female Tg.AC hemizygous and p53 haploinsufficient mice were exposed to the same concentrations for 41 weeks.

### Positive Control Mice

For each route of administration, positive control groups of 15 male and 15 female Tg.AC hemizygous mice were administered 1.25 µg TPA in 100 µL acetone (12.5 µg TPA/L solution) three times per week for 26 weeks. The positive TPA controls are included because it has been shown that a subset of Tg.AC mice may revert and become nonresponsive to tumor promotors (Honchel et al., 2001). The TPA solution was applied to the clipped dorsal skin from the mid-back to the interscapular area. Positive control mice were removed from study after the appearance of 20 or more skin papillomas and discarded.

### Source and Specification of Animals

Male and female FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous and B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY) for use in the 26-, 39- and 41-week studies. Tg.AC hemizygous mice were quarantined for 11 (drinking water) or 14 (dermal) days, and p53 haploinsufficient mice were quarantined for 12 days before the beginning of the studies. Five male and five female mice per strain were randomly selected for parasite evaluation and gross observation of disease. Tg.AC hemizygous mice were approximately 6 weeks old and p53 haploinsufficient mice were 6 to 8 weeks old at the beginning of the studies. Blood samples were collected from five male and five female sentinel mice from each study at 4 and 26 weeks, from five male and five female mice from the highest-surviving groups from each study at 39 or 41 weeks, and from designated mice on June 9, 2000. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative. Animals were housed individually. Feed and water were available ad libitum. Water consumption was measured weekly by cage during the drinking water studies. Cages and racks were rotated every 2 weeks. Further details of animal maintenance are summarized in Table 1.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings and body weights were recorded initially, weekly, and at the end of the studies. Clinical findings for dermal study mice were recorded postdosing.

In-life observations of papilloma formation on the skin were recorded weekly using the Toxicology Data Management System (TDMS). A papilloma was initially recorded as a mass. The observation “papilloma” was not entered into TDMS for a given animal until the first-observed mass was documented for 3 consecutive weeks. At the third observation, a mass wart-like in appearance was entered as a papilloma. Any new mass(es) appearing after the 3-week confirmation period for a given animal at a different site was entered into TDMS first as a mass until the third week, when it was entered as a papilloma. In a few instances, a papilloma that had been previously observed was missing, and therefore not recorded. Reappearance of a mass at a later time was entered into TDMS as a mass until the third observation week, when it was called a papilloma.

At the end of the 26-week studies, blood for hematology analysis was collected from the retroorbital sinus of all mice (except positive controls) under carbon dioxide anesthesia. Samples for hematology analysis were placed in microcollection tubes (Sarstedt, Inc., Nümbrecht, Germany) coated with potassium EDTA. Hematocrit; erythrocyte, platelet, and leukocyte counts; mean cell hemoglobin; and mean cell hemoglobin concentration were determined with a Cell-Dyn^®^ hematology analyzer (Abbott Diagnostics, Santa Clara, CA). Hemoglobin concentrations were determined photometrically using a cyanmethemoglobin procedure. Differential leukocyte counts were determined microscopically from blood smears stained with a modified Wright-Giemsa stain. A Miller Disc was used to determine reticulocyte counts from smears prepared with blood stained with new methylene blue. Mean cell volumes were determined from average red blood cell impedance pulse heights. The parameters measured are listed in Table 1.

Necropsies and microscopic evaluations were performed on all animals except the positive control groups. The heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 5 µm, and stained with hematoxylin and eosin for microscopic evaluation. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified, and the histotechnique was evaluated. The quality assessment pathologist examined all tumors and all slides from potential target organs, which included the kidney and liver of Tg.AC hemizygous mice and p53 haploinsufficient mice and the skin of Tg.AC hemizygous mice in the dermal studies.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) chairperson, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the chairperson to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

The 26-week studies had not undergone a quality assessment review prior to completion of the pathology review for the 39- and 41-week studies. For the 26-week studies, a quality assessment pathologist evaluated all tumor diagnoses from all animals and all potential target organs (both genders, both strains, all routes of administration), which included the liver and skin, using terminology and diagnostic criteria defined by the Pathology Working Group for the 39- and 41-week studies in order to maintain diagnostic consistency between the studies. The quality assessment pathologist and two NTP pathologists met to review selected examples of lesions related to chemical administration and to address any disagreements in the diagnoses made by the laboratory and quality assessment pathologists. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, the quality assessment pathologist, and the NTP pathologists.

TABLE 1 Experimental Design and Materials and Methods in the Dermal and Drinking Water Studies of Dichloroacetic Acid

Dermal Studies | Drinking Water Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice | FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice
| B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice
Animal Source
Taconic Laboratory Animals and Services, Inc. (Germantown, NY) | Taconic Laboratory Animals and Services, Inc. (Germantown, NY)
Time Held Before Studies
14 days | Tg.AC mice: 11 days
| p53 mice: 12 days
Average Age When Studies Began
6 weeks | Tg.AC mice: 6 weeks
| p53 mice: 7 to 8 weeks (males)
| 6 to 7 weeks (females)
Date of First Dose or Exposure
February 17, 2000 | Tg.AC mice: January 17, 2000
| p53 mice: January 18, 2000
Duration of Dosing or Exposure
26 or 39 weeks | 26 or 41 weeks
Date of Last Dose or Exposure
August 15, 2000 (26-week study, males) | Tg.AC mice: July 10, 2000 (26-week study, males)
August 16, 2000 (26-week study, females) | July 11, 2000 (26-week study, females)
November 15, 2000 (39-week study, males and females) | October 23, 2000 (41-week study, males)
| October 24, 2000 (41-week study, females)
| p53 mice: July 12, 2000 (26-week study, males)
| July 13, 2000 (26-week study, females)
| October 25, 2000 (41-week study, males)
| October 26, 2000 (41-week study, females)
Necropsy Dates
August 16, 2000 (26-week study, males) | Tg.AC mice: July 10, 2000 (26-week study, males)
August 17, 2000 (26-week study, females) | July 11, 2000 (26-week study, females)
November 16, 2000 (39-week study, males and females) | October 23, 2000 (41-week study, males)
| October 24, 2000 (41-week study, females)
| p53 mice: July 12, 2000 (26-week study, males)
| July 13, 2000 (26-week study, females)
| October 25, 2000 (41-week study, males)
| October 26, 2000 (41-week study, females)
Average Age at Necropsy
32 weeks (26-week study) | Tg.AC mice: 31 weeks (26-week study)
45 weeks (39-week study) | 46 weeks (26-week study)
| p53 mice: 31 to 33 weeks (26-week study, males)
| 31 to 32 weeks (26-week study, females)
| 46 to 48 weeks (41-week study, males)
| 46 to 47 weeks (41-week study, females)
Size of Study Groups
26-week study: 15 males, 15 females | 26-week study: 15 males, 15 females
39-week study: 10 males, 10 females | 41-week study: 10 males, 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as dermal studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 open formula meal (Zeigler Brothers, Inc., Gardners, PA), available ad libitum | Same as dermal studies
Water
Tap water (City of Columbus Municipal Supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Tap water (City of Columbus Municipal Supply) via amber glass bottles (Supelco, Bellefonte, PA) with stainless steel double-ball bearing sipper tubes (Ancare, Bellmore, NY) with Teflon^®^-lined septa, available ad libitum; changed weekly
Cages
Polycarbonate cages (Lab Products, Inc., Seaford, DE), changed weekly | Same as dermal studies
Bedding
Irradiated Sani-Chips^®^ hardwood chips (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly | Same as dermal studies
Rack Filters
DuPont^®^ spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as dermal studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as dermal studies
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Room air changes: 10/hour | Room air changes: 10/hour
Doses or Exposure Concentrations
0, 31.25, 125, or 500 mg/kg dichloroacetic acid 5 days per week | 0, 500, 1,000, or 2,000 mg/L dichloroacetic acid
or 1.25 µg TPA three times per week | or 1.25 µg TPA three times per week
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical observations were recorded initially, weekly, and at the end of the studies. Clinical findings were recorded postdosing. | Observed twice daily; animals were weighed and clinical observations were recorded initially, weekly, and at the end of the studies. Water consumption was recorded weekly.
Method of Sacrifice
Carbon dioxide asphyxiation | Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on all mice (except positive controls). Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus | Necropsies were performed on all mice (except positive controls). Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus
Clinical Pathology
Blood was collected from the retroorbital sinus of all mice (except positive controls) at the end of the 26-week studies for hematology. Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials | Same as dermal studies
Histopathology
Histopathology was performed on all mice except positive controls. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, brain, large intestine (cecum, colon), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, ovary, pituitary gland, skin, skin (site of application), spleen, stomach (forestomach), testis (with epididymis), thymus, thyroid gland, and uterus. | Histopathology was performed on all mice except positive controls. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, brain, large intestine (cecum, colon), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, ovary, pituitary gland, spleen, stomach (forestomach), testis (with epididymis), thymus, thyroid gland, and uterus.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958). Animals found dead of other than natural causes were censored from the survival analyses; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation and Analysis of Lesion Incidences

The incidences of neoplasms or nonneoplastic lesions are presented in Appendixes A, B, and C as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test, a procedure based on the overall proportion of affected animals, was used to determine significance (Gart et al., 1979).

The weekly in-life skin papilloma counts were evaluated by the method of Dunson et al. (2000). The model separates effects on papilloma latency and multiplicity and accommodates important features of the data, including animal-to-animal variability in the expression of the transgene as reflected in the initial tumor counts. The two key parameters are γ_1_, which measures the dose effect on incidence (number of animals with one or more papillomas during the study), and γ_2_, which measures the dose effect on multiplicity (rate of appearance of additional papillomas after the initial papilloma has occurred). The model assumes that the rate (number of additional papillomas per time period) is exponentially increasing with respect to dose and that the rate remains constant across time.

More specifically, under the model, the increase in papilloma burden from one week to the next is assumed to be distributed as a Poisson random variable. The Poisson mean is assumed to depend on an animal-specific susceptibility variable, on exposure length, and on the dose. The rate of initial papilloma occurrence is assumed to be log-linear in time. The coefficients for time are levels of dose multiplied by γ_1_ and the animal-specific susceptibility parameters. This implies that as the dose/time increases, the rate of occurrence for the first papilloma will increase exponentially relative to increases in dose/time. A value of zero for γ_1_ implies that dose is not associated with incidence (or, equivalently, the length of the latency period prior to initial onset), leaving only animal-specific characteristics to explain any variability.

After the latency period (after the first papilloma occurs), the Poisson mean changes to a rate that is only dependent on dose (that is, no animal-specific rates or dependency with time). More explicitly, the rate of occurrence of additional papillomas is assumed to be log-linear in time. A value of zero for γ_2_ implies that dose is not associated with rate of additional papilloma occurrence. A non-zero value implies that the rate of additional papillomas increases with dose in a proportional fashion.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed or exposed groups and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Hematology data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) (as modified by Williams, 1986) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1957) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973).

## Quality Assurance Methods

The 26-, 39-, and 41-week studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from the studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor.

Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al. (1992). Dichloroacetic acid was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, and TA1535 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37° C. Top agar supplemented with _L_-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37° C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of dichloroacetic acid. The high dose was limited by toxicity. All positive trials were repeated under the conditions that elicited the positive response.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

### Mouse Peripheral Blood Micronucleus Test Protocol

Detailed discussions of this assay are presented by MacGregor et al. (1990) and Witt et al. (2000). At the end of the 26-week studies, peripheral blood samples were obtained from male and female Tg.AC hemizygous and p53 haploinsufficient mice. In addition, in another study, peripheral blood samples were obtained from B6C3F_1_ mice exposed to dichloroacetic acid in drinking water (67 to 1,000 mg/L) for 3 months. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in up to 15 Tg.AC hemizygous or p53 haploinsufficient mice or 10 B6C3F_1_ mice per dose or exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs) in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within an exposure group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose or exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed or exposed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed or exposed group is less than or equal to 0.025 divided by the number of dosed or exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects. Because these studies were not repeated, the results of the micronucleus trials were accepted without replication.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary tables in the Abstract of this Report present a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.