# INTRODUCTION

DICHLOROACETIC ACID

CAS No. 79-43-6

Chemical Formula: C_2_H_2_Cl_2_O_2_ Molecular Weight: 128.9426

Synonyms: Acetic acid, dichloro; bichloracetic acid; DCA; dichlorethanoic acid; 2,2-dichloroacetic acid; dichloroethanoic acid; kyselina dichloroctova; Urner’s liquid

## Chemical and Physical Properties

Dichloroacetic acid, a clear, colorless liquid with a pungent odor and density of 1.5724 g/mL at 20° C, is formed when organic substances in water react with chlorine (Stevens et al., 1976; Hoehn et al., 1978; Rook, 1980). Dichloroacetic acid as a chlorinated organic molecule is included in the haloacetic acids class of chemicals formed as a by-product when drinking water supplies are disinfected by chlorination (Rook, 1974). Dichloroacetic acid and trichloroacetic acid are the two most abundant haloacetic acids in most water supplies (Krasner et al., 1989).

## Production, Use, and Human Exposure

The United States Environmental Protection Agency has established a maximum contaminant level of 0.060 mg/L for the five most common regulated haloacetic acids (HAA5) in community water systems serving more than 10,000 persons (40 CFR §141.64). The presence of haloacetic acids in the drinking water is believed to pose a risk to humans because haloacetic acids have been shown to cause tumors in rats and mice following long-term exposure (Bull et al., 1990; Daniel et al., 1992; DeAngelo et al., 1996; Komulainen, 2004). Haloacetic acids are widespread in the environment, not only in water supplies but also in swimming pools, soft drinks, and dump sites (NTP, 1987). The concentration of total haloacetic acids in chlorinated water supplies in the United States occasionally exceeds 0.1 mg/L (Weisel et al., 1999). Assuming that the average daily water consumption for an adult male human weighing 70 kg is 2 liters per day, intake of dichloroacetic acid could approach a maximum daily consumption of 3.0 µg/kg per day.

## Absorption, Distribution, and Excretion

Dichloroacetic acid is rapidly and completely absorbed from the stomach and intestinal tract in rodents and humans with glyoxylate, glycolate, and carbon dioxide being the major metabolites (Lin et al., 1993; Gonzales-Leon et al., 1997). In rats given 0.05 to 20 mg/kg either intravenously or by oral gavage, the elimination is so rapid that only doses above 1 mg/kg intravenously and 5 mg/kg orally provide plasma levels above detection limits of 6 ng/mL (Saghir and Schultz, 2002). Dichloroacetic acid exposure appears to induce CYP2E1 activity in both male and female rats (Yang et al., 1996).

## Toxicity

### Experimental Animals

Dichloroacetic acid is relatively nontoxic; doses of greater than 4,000 mg/kg are required for an LD_50_ in fasted mice (Yount et al., 1982).

### Humans

In a few cases, humans have been treated with dichloroacetic acid at 25 mg/kg for as long as 5 years (Stacpoole et al., 1998). Approximately 50% of the patients receiving 25 to 50 mg/kg experienced sedative effects. There have been three reported cases of peripheral neuropathy following dichloroacetic acid treatment, but all were completely reversible within 6 months following cessation of treatment (Stacpoole et al., 1998).

## Reproductive and Developmental Toxicity

### Experimental Animals

Decreased testes weights, testicular atrophy with no mature spermatozoa, and decreased spermatocytes in the seminiferous tubules were found in male Sprague-Dawley rats exposed to 1,100 mg/kg per day dichloroacetic acid in the drinking water for 90 days (Bhat et al., 1991). Doses of 0, 125, 500, or 2,000 mg/kg per day of dichloroacetic acid were administered by gavage to adult rats for 3 months (Katz et al., 1981). All males given 2,000 mg/kg and 40% of the males given 500 mg/kg had testicular germinal epithelial degeneration. In addition, all males given 2,000 mg/kg and 20% given 500 mg/kg had syncytial giant cells in the germinal epithelium. Morphologic changes were not found in reproductive tissues in females at any dose.

Male Long-Evans rats dosed by oral gavage with 0, 31.25, 62.5, or 125 mg/kg per day dichloroacetic acid for 10 weeks had increased relative liver weights at all doses (Toth et al., 1992). The absolute preputial gland and epididymal weights, but not testes weights, were decreased at all doses. The number and motility of the sperm were affected in four of 10 rats given 62 mg/kg and in nine of 10 rats given 125 mg/kg.

In beagle dogs administered 12.5 to 72 mg/kg of dichloroacetic acid in capsules for 90 days, testicular lesions were observed at 12.5 mg/kg (Cicmanec et al., 1991).

### Humans

Because dichloroacetic acid has been used therapeutically in humans, a number of individuals have been exposed to 25 mg/kg per day or greater for years. No studies reporting reproductive effects in humans exposed to dichloroacetic acid were found in the literature. While adverse birth outcomes related to chlorinated drinking water have been suggested, emphasis has been on potential trihalomethane exposures and not exposure to haloacetic acids (Nieuwenhuijsen et al., 2000).

## Neurotoxicity

### Experimental Animals

Central and peripheral neuropathy have been reported in male and female rats treated with dichloroacetic acid doses as low as 125 mg/kg per day for 10 weeks (Katz et al., 1981). Severe neuropathy has been noted in male F344 rats exposed to 2.5 to 5 g/L dichloroacetic acid in the drinking water (DeAngelo et al., 1996). In a series of studies involving adult and weanling Long-Evans and F344 rats of both sexes, doses as low as 16 mg/kg per day produced gait and grip strength changes predominantly in the hind limbs (Moser et al., 1999). In general, dichloroacetic acid was more potent when given in the drinking water than when given by oral gavage. Severe neuromuscular toxicity induced by dichloroacetic acid exposure for 6 months was not reversible, while milder neurotoxicity induced by lower concentrations and for shorter durations of exposure was reversible. The F344 rats appeared more sensitive to neurotoxicity than did the Long-Evans hooded rats. Neurotoxicity also has been induced in Wistar rats (Yount et al., 1982) and Sprague-Dawley rats (Stacpoole et al., 1990). Dogs given 50 to 100 mg/kg dichloroacetic acid for 13 weeks developed hind limb weakness and vacuolization of the myelinated tracts in both the cerebellum and cerebrum (Stacpoole et al., 1979).

### Humans

There have been three reported cases of peripheral neuropathy following dichloroacetic acid treatment, but all were completely reversible within 6 months following cessation of treatment (Stacpoole et al., 1998). In one of these cases, after reversal of symptoms with cessation, dichloroacetic acid treatment was resumed at 10 to 25 mg/kg for 2 years without further evidence of neuropathy. Sixteen weeks of approximately 50 mg/kg of dichloroacetate resulted in polyneuropathy in a young male patient; the symptoms regressed with cessation of treatment. A 13-year-old female experienced peripheral neuropathy with dichloroacetic acid treatment despite concomitant thiamine medication (Kurlemann et al., 1995). Because of these complications, dichloroacetic acid therapy for metabolic disorders in humans is not recommended (Stacpoole et al., 1979).

## Carcinogenicity

### Experimental Animals

Dichloroacetic acid appears to cause liver tumors in mice and male rats (Komulainen, 2004). Dichloroacetic acid was administered at 2.5 g/L to male F344 rats, but due to neurotoxic effects, the dose was lowered to 1 g/L after 18 weeks. Between 26 and 33 rats survived to 79 weeks, and there was a marginal increase in hepatocellular carcinomas in the highest dose group (DeAngelo et al., 1996). Male B6C3F_1_ mice exposed to 1 g/L of dichloroacetic acid in drinking water developed increased incidences of hepatocellular carcinomas and hepatocellular adenomas (Daniel et al., 1992). Male and female mice given 1 or 2 g/L of dichloroacetate in drinking water for 52 weeks developed hepatocellular adenomas and carcinomas (Bull et al., 1990). An examination of the ras protooncogene activation in dichloroacetic acid-induced liver tumors in mice suggested that dichloroacetic acid provided a selective growth advantage to spontaneously occurring mutations in the ras oncogene (Anna et al., 1994).

### Humans

Exposure to chlorinated drinking water and trihalomethanes have been associated with increased rates of bladder, colon, or rectal cancer in humans (Cantor et al., 1998; Hildesheim, et al., 1998). Reconstructing accurate and specific disinfection by-product protracted exposure histories and modeling human exposure to drinking water disinfection by-products is difficult at best. In general, epidemiology studies tend to relate cancers to trihalomethane exposures (McGeehin et al., 1993; Villanueva et al., 2003; Chevrier et al., 2004). No studies reporting associations between dichloroacetic acid exposure in the drinking water and increased human cancer risk were found in the literature.

## Genetic Toxicity

The majority of published genetic toxicity studies with dichloroacetic acid indicate that the compound is a weak mutagen in bacterial and mammalian cells in vitro. DeMarini et al. (1994) reported that dichloroacetic acid induced a weak but significant increase in plaque-forming units in the Microscreen^®^ prophage induction assay using Escherichia coli prophage lambda. In addition, in Salmonella typhimurium strain TA100, dichloroacetic acid induced a significant increase (three to fives times) in mutant colonies with and without S9 activation, using a protocol that controlled for volatility; mutational spectra analysis showed that the alterations in the hisG46 allele of the TA100 strain were primarily GC to AT transitions (DeMarini et al., 1994). Both dichloroacetic acid and its brominated analog induced DNA damage in the E. coli SOS repair assay, and both compounds were reported to be mutagenic in S. typhimurium TA100 (Giller et al., 1997); in both assays, the brominated compound was more potent than the chlorinated analogue. Recently, mutation induction in S. typhimurium strains TA98 and TA100 exposed to dichloroacetic acid in the presence of S9 activation was reported in a study comparing the relative mutagenic and cytotoxic potencies of a series of haloacetic acids (Kargalioglu et al., 2002); as in other studies, these authors reported that the brominated acetic acids investigated in their study were stronger mutagens than their chlorinated analogues. Leavitt et al. (1997) showed that administration of dichloroacetic acid in drinking water (1.0 or 3.5 g/L) for 60 weeks produced increases in mutant frequencies measured in the bacterial lacI gene in hepatocytes of transgenic male B6C3F_1_ mice; these lacI mutations were also the result of GC to AT transitions, although some transitions and transversions at TA sites within the lacI gene were also reported in this study.

Results of tests for dichloroacetic acid-induced genetic damage in mammalian cells are varied, with negative, weak positive, and positive results being reported, depending upon cell type and endpoint measured. Dichloroacetic acid, over a concentration range of 100 µg/mL to 800 µg/mL, was shown to be weakly mutagenic in L5178Y/TK^+/−^ mouse lymphoma cells in the absence of S9 activation and in the absence of any potentially confounding fluctuations in pH caused by the addition of acetic acid to the cell cultures (Harrington-Brock et al., 1998). Dichloroacetic acid was also shown to induce chromosomal aberrations in L5178Y/TK^+/−^ cells; however, no significant increases in micronuclei (surrogate indicators of numerical or structural aberrations) or aneuploidy were observed in these cells (Harrington-Brock et al., 1998).

Dichloroacetic acid did not induce DNA strand breaks in Chinese hamster ovary AS52 cells, when measured by alkaline single-cell gel electrophoresis (Comet assay) (Plewa et al., 2002), and administration of dichloroacetic acid to male B6C3F_1_ mice for 3 to 10 weeks in drinking water did not result in measurable increases in oxidative damage in hepatocytes (Parrish et al., 1996). However, in this same study, dose-related increases in 8-OH-dG in nuclear DNA of hepatocytes was observed after similar treatment of male B6C3F_1_ mice with dibromoacetic acid, confirming a stronger response in genotoxicity assays for brominated analogues compared with chlorinated ones.

Dichloroacetic acid did not induce DNA strand breaks, measured by an alkaline unwinding assay, in hepatocytes, splenocytes, or gastric epithelial cells of rats and mice treated in vivo or in primary cultures of rat and mouse hepatocytes; in addition, no DNA strand breaks were induced in human lymphoblastic leukemia cells treated in vitro with dichloroacetic acid (Chang et al., 1992).

Experiments in which dichloroacetic acid (0.5, 1.0, 2.0, or 3.5 g/L) was administered in drinking water to groups of male B6C3F_1_ mice for varying periods of time from 9 days to 31 weeks resulted in a small but statistically significant (P<0.05) dose-related increase in micronucleated polychromatic erythrocytes at the 9-day time point, but not after 28 days of exposure (Fuscoe et al., 1996). Additionally, treatment with 3.5 g/L of dichloroacetic acid for 10, 26, or 31 weeks induced a small but significant (P≤0.02) increase in micronucleated normochromatic erythrocytes (mature erythrocytes, in steady state in peripheral blood by about 4 weeks of continuous treatment) measured 31 weeks after the initiation of exposure (the 10- and 26-week treatments were stop-exposure studies). Furthermore, in these same studies, it was shown that concurrent administration of vitamin E with dichloroacetic acid did not alter induction of micronuclei in erythrocytes of exposed mice, and thus, the authors concluded that the cytogenetic effects of dichloroacetic acid were probably not the result of oxidative damage.

Additionally, DNA migration, measured by the Comet assay, was reduced (P=0.023) in blood leukocytes of male B6C3F_1_ mice treated with 3.5 g/L dichloroacetic acid in drinking water for 28 days, indicating the possibility of DNA crosslinking (Fuscoe et al., 1996).

One of the rodent metabolites of dichloroacetic acid, glyoxylic acid, was reported to be mutagenic in S. typhimurium strains TA97, TA100, and TA104 without S9 activation, and mutagenic in TA102 with S9 (Sayato et al., 1987).

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, two genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53) or a gain of oncogene function (Ha-ras) were used to determine how these animals would respond to dichloroacetic acid exposure. The Tg.AC hemizygous and p53 haploinsufficient mice have been shown to be susceptible to the rapid development of cancer and are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) and the NTP as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996; Pritchard et al., 2003).

### FVB/N-TgN(v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

The Tg.AC hemizygous transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). The Tg.AC strain of mice is hemizygous for a mutant v-Ha-ras transgene. The model was developed by Leder et al. (1990) with an inducible zeta-globin promoter driving the expression of a mutated (point mutation in codons 12 and 59) v-Ha-ras oncogene and is regarded as a genetically initiated model. With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is usually transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC hemizygous mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. 12-O-tetradecanoylphorbol-13-acetate (TPA) has been used as a positive control in NIEHS Tg.AC mouse studies to confirm the mice are responsive to carcinogens because it has been found that a subset of Tg.AC mice may revert and become nonresponsive to a tumor promoter (Honchel et al., 2001). The oral route of administration can also generate tumor responses in the skin of Tg.AC hemizygous mice and lead to squamous cell papillomas and/or carcinomas of the forestomach. To date, the appearance of either spontaneous or induced tumors has been shown to involve transgene expression. However, the mechanism of response by the Tg.AC hemizygous mouse model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Cutaneous papillomas at various sites have been reported at 3.7% and 3.8% incidence in 33-week-old control male and female Tg.AC hemizygous mice, respectively (Mahler et al., 1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice can develop odontogenic tumors as early as 33 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at an incidence of greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar-bronchiolar adenomas, salivary gland duct carcinomas, and erythroleukemia (Mahler et al.,1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current Report for the studies of dichloroacetic acid because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard et al., 2003). Tg.AC hemizygous mice may spontaneously lose a portion of the zeta-globulin promoter sequence making them unresponsive to TPA-initiated tumors (Thompson et al., 1998). Therefore, TPA positive controls were included for Tg.AC studies.

### B6.129-Trp53^tm1Brd^ (N5) Mouse Model

The heterozygous B6.129-Trp53 (N12)^tmlBrd(+/−)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein is labile and exists at very low concentrations in normal cells; mutants of p53 are expressed in high amounts in DNA damaged cells or a variety of transformed cell lines and are believed to contribute to transformation and malignancy. The p53 protein is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues may be phosphorylated or acetylated, which may determine p53 function. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site frequently occur in human cancers, and are unable to function as tumor suppressors. Alterations of the Trp53 gene occur not only as somatic mutations in human malignancies, but also as germline mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/−) has only a single functional wild-type p53 allele which provides a target for mutagens. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c).

Heterozygous p53^(+/−)^ mice develop normally and like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency.

## Study Rationale

The purpose of this study was twofold. Given the hundreds of potentially hazardous disinfection byproducts (Bull et al., 1995), usually at very low concentrations and occurring as mixtures, a more efficient process for determining safety of chemicals and chemical mixtures found in finished drinking water is needed (Boorman, et al., 1999). One objective of this study was to help determine whether the use of genetically modified mice could reduce study length and increase sensitivity for determining potential hazards of drinking water disinfection by-products compared to traditional rodent bioassays. This study was one of three studies to investigate the Tg.AC hemizygous and p53 haploinsufficient strains using drinking water by-products that had been extensively studied using traditional rodent models. The results of bromodichloromethane (NTP, 2007a) and sodium bromate (NTP, 2007b) are being reported separately. The second objective was to determine whether dichloroacetic acid exposure, which nearly uniformly causes increased incidences of mouse liver tumors, would cause similar tumors in transgenic mice considered resistant to chemicals causing mouse liver tumors (Dass et al., 1999; Spalding et al., 2000).

For the past few years, the NIEHS and the NTP have been actively evaluating genetically altered strains in toxicologic testing strategies. Based on completed evaluations, three models, the Tg.AC hemizygous (v-Ha-ras), p53-deficient (p53 haploinsufficient), and the ras H2 (cHa-ras-transgene) mice have shown potential usefulness in identifying carcinogens (Pritchard et al., 2003). This Report focuses on the Tg.AC hemizygous and p53 haploinsufficient mouse models.