# APPENDIX H WATER AND COMPOUND CONSUMPTION IN THE 26- AND 41-WEEK DRINKING WATER STUDIES OF DICHLOROACETIC ACID

TABLE H1 Water and Compound Consumption by Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 5.7 | 22.5 | 5.2 | 22.8 | 113 | 4.0 | 23.2 | 172 | 2.8 | 22.8 | 242
3 | 5.4 | 23.7 | 4.2 | 24.3 | 86 | 3.7 | 25.1 | 147 | 3.0 | 24.8 | 239
4 | 5.4 | 25.4 | 4.0 | 26.3 | 76 | 5.1 | 26.4 | 191 | 2.9 | 26.1 | 220
5 | 5.9 | 26.4 | 5.0 | 27.4 | 91 | 3.4 | 27.3 | 124 | 2.9 | 27.0 | 216
6 | 5.1 | 27.1 | 3.2 | 27.7 | 57 | 3.7 | 27.4 | 134 | 3.3 | 27.8 | 240
7 | 4.9 | 27.8 | 4.7 | 28.2 | 83 | 5.1 | 28.1 | 181 | 2.9 | 27.9 | 210
8 | 5.0 | 28.4 | 3.5 | 29.0 | 60 | 4.6 | 29.1 | 160 | 4.0 | 28.5 | 281
9 | 4.7 | 28.8 | 3.7 | 29.3 | 64 | 5.2 | 30.0 | 172 | 4.1 | 28.9 | 283
10 | 4.8 | 28.6 | 5.6 | 30.2 | 92 | 4.3 | 29.8 | 144 | 4.1 | 28.8 | 288
11 | 4.4 | 29.7 | 4.1 | 30.8 | 66 | 4.8 | 30.6 | 158 | 4.1 | 29.9 | 275
12 | 4.4 | 30.8 | 5.0 | 31.3 | 80 | 4.4 | 30.8 | 141 | 4.6 | 30.9 | 296
13 | 3.9 | 31.0 | 5.4 | 31.6 | 85 | 4.3 | 31.6 | 137 | 4.9 | 31.2 | 314
14 | 4.4 | 31.2 | 4.8 | 32.0 | 74 | 4.8 | 31.6 | 152 | 4.2 | 31.3 | 268
15 | 4.0 | 31.5 | 5.4 | 32.2 | 84 | 5.0 | 31.6 | 159 | 4.1 | 31.5 | 259
16 | 3.9 | 31.3 | 5.5 | 32.5 | 84 | 4.7 | 31.8 | 148 | 4.0 | 31.6 | 251
17 | 3.8 | 31.5 | 5.4 | 33.4 | 81 | 4.4 | 31.9 | 139 | 3.7 | 32.1 | 228
18 | 4.3 | 31.7 | 5.7 | 33.7 | 85 | 4.5 | 32.3 | 139 | 3.4 | 32.0 | 211
19 | 4.3 | 32.5 | 5.1 | 34.7 | 73 | 4.2 | 33.4 | 124 | 3.7 | 33.3 | 224
20 | 4.0 | 32.8 | 5.0 | 35.3 | 70 | 4.1 | 32.8 | 126 | 3.0 | 32.8 | 182
21 | 4.2 | 33.2 | 5.6 | 35.7 | 78 | 3.9 | 31.7 | 123 | 3.9 | 33.1 | 238
22 | 4.1 | 33.6 | 5.1 | 35.7 | 72 | 4.5 | 35.7 | 125 | 3.3 | 33.3 | 198
23 | 4.1 | 33.4 | 4.0 | 35.4 | 56 | 4.7 | 35.7 | 133 | 3.4 | 33.9 | 202
24 | 3.9 | 33.8 | 4.3 | 35.4 | 61 | 4.6 | 35.9 | 128 | 3.0 | 33.7 | 181
25 | 3.9 | 34.5 | 4.2 | 35.5 | 59 | 4.4 | 36.5 | 120 | 3.4 | 34.1 | 201
Mean for weeks
2–13 | 5.0 | 27.5 | 4.5 | 28.2 | 79 | 4.4 | 28.3 | 155 | 3.6 | 27.9 | 259
14–25 | 4.1 | 32.6 | 5.0 | 34.3 | 73 | 4.5 | 33.4 | 135 | 3.6 | 32.7 | 220

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H2 Water and Compound Consumption by Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 5.7 | 18.9 | 5.3 | 19.2 | 139 | 4.0 | 19.6 | 207 | 2.9 | 19.3 | 298
3 | 5.3 | 19.4 | 6.2 | 20.5 | 150 | 4.6 | 20.5 | 223 | 3.4 | 20.5 | 337
4 | 4.9 | 21.5 | 6.5 | 21.3 | 152 | 5.4 | 21.7 | 249 | 3.4 | 21.2 | 321
5 | 5.8 | 22.3 | 5.8 | 22.2 | 130 | 4.9 | 22.2 | 220 | 3.7 | 21.9 | 337
6 | 4.3 | 22.8 | 5.2 | 22.2 | 118 | 5.0 | 22.8 | 221 | 3.8 | 21.9 | 347
7 | 5.7 | 22.9 | 5.4 | 22.2 | 122 | 4.7 | 23.1 | 206 | 3.8 | 22.4 | 336
8 | 5.7 | 24.0 | 5.0 | 23.2 | 107 | 4.4 | 23.7 | 188 | 4.2 | 22.8 | 370
9 | 5.5 | 24.3 | 5.1 | 24.3 | 106 | 4.8 | 24.4 | 197 | 4.0 | 23.2 | 348
10 | 6.2 | 24.2 | 5.7 | 24.9 | 115 | 4.5 | 24.4 | 183 | 4.0 | 22.6 | 350
11 | 6.0 | 24.6 | 5.2 | 24.9 | 104 | 4.4 | 25.1 | 175 | 4.1 | 23.1 | 350
12 | 5.8 | 25.1 | 5.2 | 24.7 | 106 | 5.2 | 24.8 | 208 | 4.4 | 23.9 | 368
13 | 5.7 | 25.5 | 6.4 | 25.2 | 127 | 4.9 | 24.8 | 196 | 4.0 | 24.1 | 329
14 | 5.3 | 25.5 | 5.7 | 25.9 | 110 | 5.2 | 25.2 | 206 | 3.5 | 24.6 | 283
15 | 5.1 | 26.0 | 5.2 | 26.2 | 99 | 4.6 | 25.3 | 182 | 3.5 | 24.9 | 281
16 | 4.9 | 26.6 | 4.5 | 26.5 | 85 | 3.8 | 25.3 | 151 | 3.3 | 25.0 | 261
17 | 5.1 | 27.3 | 5.8 | 27.2 | 107 | 4.1 | 25.3 | 162 | 3.3 | 24.7 | 269
18 | 4.9 | 27.3 | 4.7 | 27.4 | 86 | 4.4 | 25.7 | 172 | 3.3 | 24.6 | 271
19 | 4.7 | 27.6 | 4.8 | 29.6 | 81 | 4.6 | 25.8 | 179 | 3.2 | 25.2 | 254
20 | 5.0 | 28.0 | 4.4 | 30.1 | 73 | 3.9 | 27.2 | 143 | 3.1 | 25.2 | 250
21 | 4.7 | 29.1 | 4.3 | 29.7 | 73 | 3.6 | 27.2 | 131 | 3.5 | 25.2 | 276
22 | 4.8 | 29.4 | 4.2 | 28.7 | 73 | 3.7 | 27.4 | 136 | 3.0 | 25.9 | 228
23 | 4.8 | 29.9 | 4.8 | 30.5 | 78 | 3.4 | 28.2 | 121 | 3.1 | 25.9 | 237
24 | 5.0 | 30.2 | 3.6 | 30.5 | 59 | 3.4 | 28.4 | 119 | 3.1 | 26.7 | 231
25 | 4.4 | 30.7 | 4.5 | 32.2 | 70 | 3.8 | 28.8 | 131 | 3.1 | 28.0 | 223
Mean for weeks
2–13 | 5.5 | 23.0 | 5.6 | 22.9 | 123 | 4.7 | 23.1 | 206 | 3.8 | 22.2 | 341
14–25 | 4.9 | 28.1 | 4.7 | 28.7 | 83 | 4.0 | 26.7 | 153 | 3.2 | 25.5 | 255

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H3 Water and Compound Consumption by Male Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 6.1 | 22.7 | 4.9 | 22.3 | 109 | 3.9 | 22.8 | 169 | 2.7 | 23.0 | 233
3 | 4.4 | 24.4 | 5.3 | 24.8 | 107 | 4.2 | 23.8 | 177 | 2.6 | 24.6 | 214
4 | 5.4 | 25.2 | | | | 4.8 | 25.3 | 190 | 3.2 | 25.7 | 249
5 | 4.9 | 27.5 | | | | 3.3 | 26.2 | 124 | 3.0 | 26.6 | 229
6 | 5.9 | 28.7 | | | | 5.2 | 27.3 | 191 | 3.8 | 27.7 | 273
7 | 5.0 | 28.6 | | | | 5.2 | 26.9 | 192 | 4.5 | 28.1 | 320
8 | 4.6 | 29.3 | 3.7 | 28.6 | 65 | 5.7 | 28.0 | 202 | 5.2 | 29.1 | 356
9 | 5.0 | 30.3 | | | | 4.8 | 28.2 | 171 | 4.9 | 29.6 | 329
10 | 6.0 | 31.2 | | | | 5.2 | 28.8 | 179 | 4.6 | 29.3 | 312
11 | 5.0 | 31.6 | | | | 5.2 | 29.4 | 178 | 4.9 | 29.9 | 329
12 | 5.2 | 32.5 | | | | 4.7 | 29.4 | 159 | 4.7 | 30.1 | 310
13 | 4.5 | 32.7 | 5.2 | 31.0 | 83 | 5.4 | 30.3 | 179 | 5.1 | 30.7 | 335
14 | 4.3 | 33.7 | 5.6 | 31.7 | 89 | 5.0 | 30.7 | 163 | 3.3 | 30.8 | 213
15 | 4.1 | 33.9 | | | | 3.6 | 30.9 | 117 | 5.1 | 31.4 | 324
16 | 4.6 | 34.4 | 4.6 | 32.6 | 71 | 5.1 | 31.2 | 163 | 3.8 | 31.6 | 242
17 | 4.7 | 35.2 | | | | 4.1 | 31.9 | 129 | 4.6 | 32.8 | 279
18 | 4.2 | 35.6 | 4.6 | 33.7 | 69 | 4.9 | 32.1 | 154 | 3.4 | 32.3 | 212
19 | 4.2 | 36.4 | 7.6 | 34.1 | 111 | 5.3 | 32.8 | 162 | 3.6 | 32.8 | 218
20 | 4.0 | 36.8 | 5.7 | 34.2 | 83 | 5.4 | 33.3 | 163 | 3.9 | 33.1 | 234
21 | 4.2 | 37.5 | 5.0 | 34.0 | 73 | 5.9 | 33.7 | 175 | 4.0 | 34.1 | 237
22 | 4.0 | 37.7 | 5.4 | 34.2 | 79 | 4.0 | 34.2 | 118 | 3.6 | 34.4 | 209
23 | 3.9 | 37.4 | 4.4 | 36.3 | 61 | 4.6 | 34.3 | 135 | 3.3 | 34.2 | 194
24 | 3.5 | 37.9 | 3.9 | 35.9 | 54 | 4.6 | 35.1 | 131 | 2.9 | 34.9 | 168
25 | 4.4 | 38.0 | 4.8 | 37.1 | 64 | 4.5 | 35.2 | 129 | 3.2 | 35.7 | 178
26 | 4.2 | 38.5 | 4.9 | 36.6 | 67 | 3.9 | 35.0 | 111 | 3.3 | 35.8 | 185
27 | 4.0 | 38.4 | 4.9 | 38.2 | 64 | 4.2 | 35.2 | 119 | 3.6 | 35.7 | 202
28 | 3.8 | 39.0 | 4.9 | 37.4 | 65 | 5.0 | 35.6 | 140 | 3.8 | 35.8 | 211
29 | 4.0 | 38.2 | 4.0 | 36.9 | 54 | 4.7 | 34.9 | 134 | 3.3 | 34.9 | 189
30 | 4.3 | 38.7 | 4.1 | 37.4 | 55 | 4.7 | 35.4 | 134 | 3.1 | 35.6 | 172
31 | 4.3 | 39.0 | 4.8 | 37.6 | 64 | 5.1 | 36.0 | 141 | 2.9 | 35.7 | 164
32 | 4.0 | 39.2 | 5.1 | 38.4 | 66 | 3.8 | 36.6 | 104 | 3.1 | 36.1 | 172
33 | 6.2 | 39.9 | 5.0 | 39.0 | 64 | 4.5 | 37.0 | 121 | 3.2 | 36.1 | 177
34 | 4.5 | 39.5 | 5.4 | 38.1 | 70 | 4.5 | 36.8 | 122 | 3.2 | 35.6 | 180
35 | 5.0 | 40.2 | 5.0 | 38.7 | 65 | 4.3 | 36.2 | 118 | 3.0 | 35.2 | 172
36 | 5.0 | 40.4 | 4.6 | 37.2 | 62 | 5.2 | 36.4 | 144 | 3.1 | 34.8 | 179
37 | 4.1 | 40.1 | 3.5 | 37.1 | 47 | 5.0 | 36.0 | 140 | 2.8 | 34.7 | 160
38 | 6.4 | 40.8 | 5.3 | 35.8 | 74 | 4.6 | 36.4 | 126 | 4.2 | 35.0 | 243
39 | 4.6 | 39.6 | 6.4 | 37.3 | 86 | 4.0 | 36.4 | 110 | 3.9 | 35.0 | 221
40 | 4.2 | 39.2 | 5.0 | 37.4 | 67 | 5.0 | 36.4 | 138 | 2.7 | 34.4 | 156
Mean for weeks
2–13 | 5.2 | 28.7 | 4.7 | 26.7 | 91 | 4.8 | 27.2 | 176 | 4.1 | 27.9 | 291
14–40 | 4.4 | 38.0 | 5.0 | 36.3 | 69 | 4.7 | 34.6 | 135 | 3.5 | 34.4 | 203

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H4 Water and Compound Consumption by Female Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 5.3 | 19.0 | 3.0 | 18.5 | 81 | 5.8 | 19.0 | 308 | 3.1 | 19.3 | 320
3 | 6.2 | 20.2 | 4.1 | 20.2 | 102 | 5.1 | 20.3 | 251 | 3.7 | 20.5 | 358
4 | 4.9 | 21.6 | 5.4 | 21.0 | 129 | 5.4 | 21.3 | 253 | 3.1 | 21.3 | 294
5 | 5.5 | 22.3 | | | | 5.9 | 22.1 | 265 | 2.9 | 22.2 | 257
6 | | | 5.3 | 23.1 | 114 | 7.0 | 23.0 | 304 | 4.1 | 22.7 | 360
7 | | | 3.6 | 23.1 | 78 | 4.8 | 23.3 | 206 | 3.3 | 22.8 | 288
8 | 6.7 | 23.8 | 6.4 | 23.9 | 133 | 5.6 | 24.2 | 233 | 4.2 | 23.2 | 359
9 | 5.8 | 24.0 | 5.6 | 24.1 | 116 | 6.0 | 24.2 | 248 | 4.6 | 23.7 | 390
10 | 6.1 | 24.0 | 4.5 | 23.8 | 94 | 5.2 | 24.3 | 214 | 3.9 | 23.2 | 340
11 | 6.2 | 25.1 | 5.8 | 24.9 | 117 | 5.0 | 24.5 | 205 | 4.0 | 24.5 | 323
12 | 5.6 | 24.9 | 4.9 | 24.3 | 102 | 5.5 | 25.0 | 221 | 2.9 | 24.8 | 230
13 | 5.4 | 26.2 | 6.0 | 25.3 | 119 | 5.1 | 25.1 | 201 | 3.6 | 25.4 | 280
14 | 4.8 | 27.3 | 5.5 | 25.5 | 107 | 4.7 | 25.6 | 183 | 3.9 | 25.0 | 311
15 | 4.9 | 26.0 | 4.9 | 24.5 | 99 | 4.8 | 25.5 | 187 | 4.1 | 24.8 | 327
16 | 4.8 | 26.7 | 5.9 | 25.0 | 117 | 6.0 | 26.0 | 229 | 3.3 | 25.5 | 256
17 | 4.5 | 27.3 | 6.0 | 25.7 | 117 | 5.3 | 26.4 | 200 | 4.6 | 26.0 | 353
18 | 5.1 | 26.7 | | | | 4.9 | 26.1 | 187 | 4.0 | 26.5 | 305
19 | 5.1 | 27.5 | 5.6 | 26.9 | 104 | 4.6 | 27.3 | 168 | 3.2 | 26.6 | 242
20 | 4.9 | 28.4 | 4.7 | 27.6 | 86 | 3.8 | 27.7 | 139 | 4.2 | 27.2 | 310
21 | 4.0 | 28.1 | 5.9 | 27.2 | 108 | 4.9 | 27.5 | 177 | 4.2 | 26.9 | 309
22 | 4.3 | 28.6 | 5.1 | 27.6 | 92 | 3.8 | 27.7 | 139 | 3.0 | 27.6 | 218
23 | 5.8 | 29.2 | 4.5 | 27.7 | 82 | 4.6 | 28.4 | 163 | 3.5 | 27.9 | 252
24 | 5.7 | 28.4 | 4.3 | 28.2 | 76 | 4.0 | 28.4 | 139 | 3.3 | 28.3 | 233
25 | 4.8 | 29.8 | 4.8 | 28.4 | 85 | 4.8 | 28.6 | 168 | 3.7 | 28.5 | 259
26 | 5.9 | 30.2 | 5.1 | 28.1 | 91 | 4.4 | 27.9 | 156 | 3.4 | 28.9 | 235
27 | 5.2 | 31.3 | 5.5 | 29.6 | 92 | 4.5 | 30.0 | 151 | 3.2 | 28.9 | 223
28 | 4.4 | 31.5 | 4.2 | 29.6 | 71 | 4.8 | 30.2 | 159 | 3.3 | 29.6 | 222
29 | 4.7 | 31.9 | 4.2 | 28.5 | 73 | 4.6 | 29.9 | 155 | 3.4 | 29.7 | 228
30 | 4.5 | 32.8 | 5.2 | 30.3 | 86 | 4.6 | 30.1 | 152 | 3.0 | 30.0 | 198
31 | 5.1 | 34.0 | 4.4 | 31.0 | 71 | 4.7 | 29.9 | 158 | 3.0 | 30.2 | 200
32 | 4.8 | 33.6 | 4.6 | 31.0 | 74 | 3.6 | 31.0 | 118 | 2.9 | 30.3 | 190
33 | 4.7 | 33.3 | 5.4 | 31.7 | 84 | 4.7 | 30.9 | 151 | 2.6 | 30.1 | 172
34 | 5.0 | 34.9 | 4.2 | 32.2 | 65 | 5.8 | 31.5 | 185 | 2.8 | 30.2 | 183
35 | 4.2 | 35.7 | 3.9 | 32.0 | 60 | 4.4 | 30.8 | 143 | 2.7 | 30.2 | 178
36 | 3.7 | 36.1 | 5.5 | 32.1 | 86 | 4.1 | 30.4 | 134 | 2.9 | 29.7 | 194
37 | 3.8 | 35.4 | 4.8 | 32.1 | 74 | 4.6 | 30.0 | 152 | 2.7 | 27.6 | 197
38 | 4.0 | 36.3 | 4.7 | 33.2 | 71 | 4.2 | 29.1 | 146 | 3.2 | 28.7 | 222
39 | 3.9 | 35.1 | 4.1 | 33.8 | 61 | 3.7 | 30.3 | 121 | 3.6 | 28.1 | 258
40 | 5.2 | 34.9 | 4.1 | 33.6 | 60 | 4.8 | 30.1 | 158 | 3.2 | 27.9 | 230
Mean for weeks
2–13 | 5.8 | 23.1 | 5.0 | 22.9 | 108 | 5.5 | 23.0 | 242 | 3.6 | 22.8 | 317
14–40 | 4.7 | 31.1 | 4.9 | 29.4 | 84 | 4.6 | 28.8 | 160 | 3.4 | 28.2 | 241

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H5 Water and Compound Consumption by Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/mg) | Water (g/day) | Body Weight (g) | Dose (mg/mg)
2 | 3.3 | 24.1 | 3.2 | 24.0 | 66 | 2.8 | 23.7 | 118 | 2.4 | 22.8 | 207
3 | 3.0 | 25.1 | 3.0 | 24.8 | 61 | 2.5 | 23.8 | 106 | 2.2 | 23.6 | 189
4 | 3.0 | 26.4 | 3.0 | 26.2 | 57 | 2.7 | 25.4 | 107 | 2.1 | 24.3 | 176
5 | 3.1 | 27.8 | 3.0 | 27.6 | 55 | 2.6 | 26.1 | 100 | 2.1 | 25.1 | 166
6 | 3.1 | 28.9 | 3.0 | 28.5 | 52 | 2.6 | 26.6 | 97 | 2.1 | 25.5 | 168
7 | 3.1 | 30.7 | 2.9 | 29.8 | 49 | 2.7 | 27.9 | 95 | 1.9 | 25.9 | 148
8 | 3.1 | 31.9 | 2.9 | 30.7 | 48 | 2.6 | 28.6 | 93 | 2.2 | 26.5 | 166
9 | 3.1 | 33.3 | 3.1 | 31.7 | 48 | 2.5 | 29.2 | 87 | 2.1 | 27.1 | 158
10 | 3.3 | 34.7 | 3.1 | 33.2 | 46 | 2.6 | 29.8 | 86 | 2.1 | 27.4 | 152
11 | 3.2 | 36.2 | 2.9 | 34.0 | 42 | 2.5 | 30.5 | 82 | 2.1 | 27.9 | 148
12 | 3.4 | 37.4 | 3.1 | 35.2 | 44 | 2.5 | 31.1 | 81 | 2.0 | 28.4 | 141
13 | 3.3 | 38.6 | 3.1 | 36.2 | 42 | 2.4 | 31.1 | 78 | 1.9 | 28.6 | 136
14 | 3.6 | 39.5 | 3.3 | 37.1 | 45 | 2.5 | 31.5 | 79 | 2.1 | 29.2 | 145
15 | 3.5 | 40.9 | 3.0 | 38.4 | 40 | 2.6 | 32.5 | 80 | 2.0 | 29.4 | 134
16 | 3.5 | 41.4 | 3.1 | 38.6 | 40 | 2.5 | 32.4 | 77 | 2.3 | 29.5 | 156
17 | 3.8 | 42.1 | 3.1 | 39.8 | 39 | 2.5 | 33.1 | 76 | 1.9 | 29.4 | 132
18 | 3.6 | 43.4 | 3.0 | 40.6 | 37 | 2.5 | 33.8 | 73 | 2.1 | 30.5 | 140
19 | 3.6 | 44.6 | 3.2 | 41.7 | 38 | 2.5 | 34.6 | 73 | 2.0 | 31.1 | 132
20 | 3.6 | 44.9 | 3.1 | 42.2 | 37 | 2.5 | 35.0 | 71 | 2.0 | 31.5 | 130
21 | 3.6 | 45.5 | 3.0 | 43.2 | 35 | 2.5 | 35.6 | 70 | 2.1 | 31.8 | 129
22 | 3.5 | 45.8 | 3.0 | 43.5 | 35 | 2.4 | 35.8 | 67 | 2.1 | 32.2 | 129
23 | 3.7 | 46.2 | 3.1 | 44.0 | 35 | 2.4 | 36.1 | 66 | 2.0 | 32.4 | 123
24 | 3.6 | 46.7 | 3.2 | 44.4 | 36 | 2.5 | 36.8 | 67 | 2.1 | 33.1 | 126
25 | 3.7 | 46.9 | 3.0 | 44.6 | 34 | 2.3 | 36.6 | 64 | 2.0 | 32.3 | 127
Mean for weeks
2–13 | 3.2 | 31.3 | 3.0 | 30.2 | 51 | 2.6 | 27.8 | 94 | 2.1 | 26.1 | 163
14–25 | 3.6 | 44.0 | 3.1 | 41.5 | 37 | 2.5 | 34.5 | 72 | 2.1 | 31.0 | 134

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H6 Water and Compound Consumption by Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 3.9 | 19.5 | 3.8 | 19.6 | 96 | 3.6 | 19.5 | 185 | 2.6 | 18.5 | 277
3 | 4.0 | 19.9 | 3.9 | 20.1 | 96 | 3.3 | 19.7 | 166 | 2.3 | 18.7 | 246
4 | 3.9 | 20.9 | 4.0 | 20.6 | 97 | 3.4 | 20.3 | 169 | 2.4 | 19.6 | 247
5 | 4.1 | 21.5 | 4.4 | 21.3 | 103 | 3.3 | 20.9 | 160 | 2.5 | 20.3 | 245
6 | 4.2 | 21.7 | 4.0 | 21.4 | 95 | 3.4 | 20.9 | 164 | 2.5 | 20.7 | 244
7 | 4.0 | 21.9 | 3.7 | 21.7 | 85 | 3.4 | 21.5 | 156 | 2.4 | 21.3 | 230
8 | 4.1 | 23.0 | 4.1 | 22.6 | 90 | 3.3 | 22.3 | 146 | 2.5 | 22.0 | 224
9 | 3.9 | 23.3 | 3.9 | 22.9 | 86 | 3.0 | 21.3 | 141 | 2.4 | 21.8 | 216
10 | 4.2 | 23.2 | 3.6 | 22.3 | 81 | 3.6 | 22.2 | 162 | 2.7 | 22.4 | 237
11 | 3.9 | 23.7 | 3.9 | 23.1 | 84 | 3.2 | 22.5 | 141 | 2.6 | 22.2 | 230
12 | 4.1 | 24.5 | 4.0 | 23.9 | 84 | 3.2 | 22.9 | 140 | 2.5 | 22.8 | 218
13 | 4.1 | 24.3 | 3.9 | 23.9 | 82 | 3.1 | 22.8 | 137 | 2.3 | 22.7 | 204
14 | 4.3 | 24.7 | 4.5 | 24.5 | 91 | 3.4 | 23.3 | 146 | 2.3 | 22.8 | 202
15 | 4.1 | 25.3 | 3.9 | 24.7 | 79 | 3.3 | 23.6 | 142 | 2.5 | 23.4 | 216
16 | 4.6 | 25.5 | 4.3 | 24.6 | 87 | 3.2 | 23.7 | 134 | 2.7 | 23.4 | 233
17 | 3.8 | 24.6 | 3.7 | 24.8 | 74 | 3.0 | 23.2 | 128 | 2.7 | 22.6 | 242
18 | 4.6 | 26.8 | 3.7 | 25.3 | 74 | 3.4 | 24.1 | 141 | 2.4 | 23.7 | 204
19 | 4.2 | 27.0 | 3.8 | 26.3 | 73 | 3.2 | 24.3 | 131 | 2.4 | 23.8 | 198
20 | 4.5 | 27.4 | 3.7 | 26.4 | 69 | 3.2 | 24.3 | 133 | 2.6 | 24.3 | 213
21 | 4.7 | 28.1 | 3.8 | 27.5 | 68 | 3.2 | 24.6 | 130 | 2.4 | 24.5 | 196
22 | 4.5 | 28.1 | 3.8 | 27.3 | 70 | 3.3 | 24.6 | 133 | 2.5 | 24.4 | 201
23 | 4.3 | 29.1 | 3.8 | 27.6 | 68 | 3.0 | 24.5 | 121 | 2.5 | 24.4 | 203
24 | 4.0 | 29.2 | 4.1 | 27.9 | 73 | 3.2 | 24.6 | 129 | 2.4 | 24.7 | 195
25 | 4.2 | 30.0 | 3.9 | 28.5 | 68 | 3.0 | 24.9 | 122 | 2.4 | 24.7 | 198
Mean for weeks
2–13 | 4.0 | 22.3 | 3.9 | 21.9 | 90 | 3.3 | 21.4 | 155 | 2.5 | 21.1 | 235
14–25 | 4.3 | 27.2 | 3.9 | 26.3 | 75 | 3.2 | 24.1 | 133 | 2.5 | 23.9 | 208

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H7 Water and Compound Consumption by Male p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 3.8 | 24.4 | 3.0 | 23.7 | 63 | 2.9 | 23.7 | 124 | 2.2 | 22.8 | 194
3 | 3.5 | 24.9 | 2.9 | 24.6 | 59 | 2.6 | 24.0 | 109 | 2.1 | 23.5 | 179
4 | 3.7 | 27.1 | 3.0 | 25.6 | 58 | 2.9 | 25.2 | 113 | 2.3 | 24.6 | 188
5 | 3.4 | 28.2 | 3.1 | 26.6 | 58 | 2.7 | 25.9 | 106 | 2.2 | 25.4 | 176
6 | 3.6 | 29.4 | 3.3 | 27.6 | 60 | 2.6 | 26.4 | 100 | 2.3 | 26.0 | 173
7 | 3.4 | 30.9 | 3.0 | 27.9 | 53 | 2.7 | 27.1 | 99 | 2.1 | 26.6 | 158
8 | 3.3 | 32.5 | 3.1 | 29.6 | 53 | 2.5 | 27.6 | 91 | 2.0 | 27.3 | 149
9 | 3.2 | 34.0 | 3.2 | 30.4 | 53 | 2.4 | 27.8 | 87 | 2.0 | 27.5 | 143
10 | 3.4 | 34.3 | 3.1 | 31.6 | 50 | 2.7 | 28.2 | 94 | 1.9 | 28.0 | 137
11 | 3.4 | 36.3 | 2.8 | 31.9 | 44 | 2.5 | 28.7 | 86 | 1.9 | 28.0 | 134
12 | 3.4 | 37.2 | 3.1 | 33.2 | 47 | 2.4 | 29.4 | 82 | 2.0 | 28.8 | 140
13 | 3.6 | 38.6 | 3.3 | 34.4 | 47 | 2.5 | 29.8 | 84 | 2.1 | 29.2 | 141
14 | 3.5 | 39.7 | 3.5 | 35.5 | 49 | 2.4 | 30.4 | 80 | 2.1 | 30.0 | 138
15 | 3.6 | 40.9 | 3.2 | 35.8 | 45 | 2.5 | 30.6 | 81 | 2.0 | 30.4 | 134
16 | 3.5 | 41.8 | 3.4 | 36.9 | 46 | 2.5 | 30.5 | 83 | 2.3 | 30.9 | 148
17 | 3.3 | 42.4 | 3.4 | 37.4 | 45 | 2.2 | 30.6 | 72 | 2.0 | 29.7 | 136
18 | 3.5 | 43.4 | 3.3 | 38.0 | 43 | 2.5 | 31.0 | 79 | 2.3 | 31.5 | 144
19 | 3.5 | 44.0 | 3.6 | 38.8 | 47 | 2.5 | 31.3 | 81 | 2.1 | 32.0 | 133
20 | 3.5 | 45.0 | 3.4 | 39.7 | 43 | 2.5 | 31.9 | 79 | 2.1 | 32.4 | 130
21 | 3.5 | 45.5 | 3.2 | 40.2 | 40 | 2.6 | 32.5 | 78 | 2.1 | 32.4 | 131
22 | 3.5 | 45.9 | 3.2 | 40.5 | 40 | 2.4 | 32.8 | 74 | 2.1 | 32.9 | 127
23 | 3.8 | 46.8 | 3.5 | 41.6 | 42 | 2.5 | 33.6 | 75 | 2.1 | 33.7 | 127
24 | 3.7 | 47.3 | 3.2 | 42.2 | 38 | 2.5 | 34.5 | 73 | 2.2 | 34.2 | 127
25 | 3.8 | 47.3 | 3.3 | 42.1 | 39 | 2.4 | 33.8 | 70 | 2.1 | 33.8 | 124
26 | 3.8 | 47.4 | 3.2 | 42.5 | 38 | 2.4 | 33.6 | 70 | 2.0 | 33.4 | 118
27 | 3.7 | 47.7 | 3.1 | 42.6 | 37 | 2.3 | 33.8 | 68 | 2.0 | 33.4 | 120
28 | 3.9 | 48.3 | 3.2 | 42.7 | 38 | 2.4 | 33.8 | 70 | 2.1 | 33.4 | 124
29 | 3.9 | 48.4 | 3.3 | 42.8 | 38 | 2.4 | 33.6 | 71 | 2.0 | 33.2 | 120
30 | 4.1 | 49.1 | 3.6 | 43.8 | 42 | 2.7 | 34.3 | 80 | 2.4 | 34.1 | 141
31 | 4.2 | 49.5 | 3.5 | 44.1 | 40 | 2.8 | 34.4 | 81 | 2.3 | 34.4 | 136
32 | 4.0 | 50.0 | 3.5 | 45.1 | 39 | 2.7 | 35.3 | 78 | 2.4 | 34.8 | 138
33 | 4.3 | 50.6 | 3.6 | 45.4 | 40 | 2.5 | 35.5 | 72 | 2.2 | 34.8 | 127
34 | 4.3 | 50.5 | 3.4 | 45.9 | 37 | 2.3 | 35.0 | 67 | 1.8 | 34.0 | 108
35 | 4.2 | 50.3 | 3.3 | 46.1 | 36 | 2.3 | 34.0 | 67 | 1.9 | 33.5 | 113
36 | 4.4 | 50.9 | 3.5 | 46.2 | 38 | 2.5 | 34.3 | 73 | 2.0 | 33.7 | 120
37 | 4.3 | 50.8 | 3.4 | 45.5 | 38 | 2.3 | 33.2 | 69 | 2.0 | 33.3 | 119
38 | 4.4 | 51.1 | 3.6 | 44.7 | 40 | 2.6 | 32.9 | 79 | 2.3 | 34.1 | 135
39 | 3.9 | 50.0 | 3.6 | 45.6 | 40 | 2.7 | 34.2 | 79 | 2.5 | 34.1 | 148
40 | 5.0 | 51.0 | 4.0 | 45.9 | 44 | 2.5 | 33.8 | 73 | 2.3 | 35.0 | 130
Mean for weeks
2–13 | 3.5 | 31.5 | 3.1 | 28.9 | 54 | 2.6 | 27.0 | 98 | 2.1 | 26.5 | 159
14–40 | 3.9 | 47.2 | 3.4 | 42.1 | 41 | 2.5 | 33.2 | 75 | 2.1 | 33.1 | 129

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day

TABLE H8 Water and Compound Consumption by Female p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid

Week | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 4.0 | 19.5 | 3.7 | 19.1 | 97 | 3.5 | 19.1 | 181 | 2.6 | 18.5 | 284
3 | 3.7 | 20.1 | 3.6 | 19.6 | 93 | 3.2 | 19.7 | 162 | 2.5 | 19.3 | 260
4 | 3.8 | 21.2 | 4.2 | 21.1 | 99 | 3.0 | 20.2 | 151 | 2.6 | 19.9 | 259
5 | 3.7 | 21.9 | 3.7 | 22.1 | 83 | 3.2 | 20.8 | 156 | 2.5 | 20.7 | 237
6 | 3.9 | 22.1 | 3.8 | 22.4 | 86 | 3.9 | 20.9 | 187 | 2.7 | 21.0 | 260
7 | 3.8 | 22.3 | 3.4 | 22.6 | 76 | 3.2 | 20.7 | 155 | 2.5 | 21.1 | 241
8 | 3.7 | 23.2 | 3.6 | 23.4 | 77 | 3.4 | 21.6 | 158 | 2.8 | 21.5 | 257
9 | 3.7 | 23.8 | 3.7 | 23.6 | 78 | 3.3 | 21.7 | 151 | 2.8 | 21.8 | 261
10 | 4.0 | 23.0 | 3.8 | 24.1 | 80 | 3.2 | 21.9 | 147 | 2.7 | 22.0 | 246
11 | 3.9 | 24.6 | 3.6 | 24.6 | 73 | 3.2 | 22.1 | 145 | 2.6 | 22.3 | 236
12 | 3.8 | 24.9 | 3.3 | 25.4 | 66 | 3.3 | 22.5 | 146 | 2.8 | 22.7 | 251
13 | 4.1 | 25.4 | 3.8 | 26.0 | 72 | 3.3 | 22.9 | 143 | 2.7 | 22.8 | 238
14 | 4.3 | 26.4 | 3.7 | 26.7 | 68 | 3.2 | 23.0 | 137 | 2.6 | 23.6 | 218
15 | 4.3 | 27.4 | 3.5 | 26.8 | 66 | 3.1 | 23.2 | 135 | 2.5 | 23.4 | 215
16 | 4.3 | 27.6 | 3.7 | 27.5 | 67 | 3.4 | 23.2 | 148 | 2.7 | 23.7 | 232
17 | 3.5 | 27.1 | 3.7 | 27.0 | 69 | 3.0 | 22.7 | 132 | 2.8 | 23.0 | 239
18 | 4.2 | 28.3 | 4.0 | 27.5 | 73 | 3.7 | 23.7 | 158 | 2.7 | 23.6 | 226
19 | 3.9 | 29.2 | 4.0 | 27.8 | 71 | 3.4 | 24.0 | 142 | 2.4 | 23.9 | 202
20 | 3.7 | 28.8 | 3.8 | 28.5 | 66 | 3.6 | 23.8 | 153 | 2.6 | 24.0 | 214
21 | 4.3 | 30.3 | 3.6 | 29.4 | 62 | 3.4 | 24.6 | 140 | 2.7 | 24.5 | 217
22 | 3.8 | 30.8 | 3.4 | 29.8 | 58 | 3.4 | 24.6 | 139 | 2.6 | 24.6 | 214
23 | 4.0 | 31.6 | 3.6 | 30.6 | 58 | 3.6 | 25.1 | 141 | 2.6 | 24.9 | 212
24 | 3.9 | 32.3 | 3.5 | 31.1 | 57 | 3.3 | 25.3 | 132 | 2.7 | 25.1 | 217
25 | 3.9 | 32.8 | 3.7 | 31.3 | 60 | 3.4 | 25.1 | 137 | 2.6 | 24.7 | 212
26 | 3.6 | 33.2 | 3.4 | 30.8 | 56 | 3.1 | 25.3 | 122 | 2.6 | 24.6 | 211
27 | 3.7 | 33.4 | 3.5 | 31.7 | 55 | 3.1 | 25.3 | 121 | 2.5 | 24.5 | 205
28 | 3.9 | 34.1 | 3.2 | 31.9 | 51 | 3.3 | 25.3 | 132 | 2.3 | 24.6 | 189
29 | 3.9 | 34.9 | 3.3 | 32.9 | 50 | 3.5 | 25.1 | 141 | 2.2 | 25.3 | 177
30 | 4.1 | 36.8 | 3.6 | 33.8 | 53 | 3.5 | 25.9 | 136 | 2.5 | 25.7 | 195
31 | 4.0 | 37.6 | 3.6 | 33.7 | 53 | 3.5 | 25.9 | 136 | 2.8 | 25.3 | 219
32 | 4.0 | 38.5 | 3.6 | 34.7 | 52 | 3.4 | 26.3 | 128 | 2.8 | 25.6 | 219
33 | 3.9 | 38.7 | 3.6 | 34.6 | 53 | 3.5 | 26.3 | 134 | 2.6 | 25.6 | 206
34 | 4.2 | 39.8 | 3.6 | 35.6 | 50 | 3.2 | 26.2 | 123 | 2.4 | 25.3 | 186
35 | 4.5 | 40.1 | 3.9 | 36.0 | 55 | 3.0 | 25.9 | 117 | 2.3 | 25.4 | 181
36 | 4.3 | 40.4 | 4.0 | 36.8 | 54 | 3.2 | 26.2 | 123 | 2.4 | 25.1 | 189
37 | 3.9 | 40.7 | 3.5 | 35.9 | 49 | 3.2 | 26.4 | 122 | 2.5 | 25.5 | 196
38 | 4.1 | 41.3 | 3.5 | 35.4 | 50 | 3.5 | 26.8 | 129 | 2.4 | 25.9 | 185
39 | 4.2 | 42.5 | 3.6 | 35.8 | 51 | 3.8 | 26.0 | 147 | 2.3 | 25.3 | 186
40 | 4.4 | 43.3 | 3.8 | 37.7 | 50 | 3.7 | 27.1 | 136 | 2.6 | 26.1 | 197
Mean for weeks
2–13 | 3.9 | 22.7 | 3.7 | 22.8 | 82 | 3.3 | 21.2 | 157 | 2.7 | 21.1 | 253
14–40 | 4.0 | 34.4 | 3.6 | 31.9 | 58 | 3.4 | 25.1 | 135 | 2.5 | 24.8 | 206

a Grams of drinking water consumed per animal per day

b Milligrams of dichloroacetic acid consumed per kilogram body weight per day