# APPENDIX G CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Dichloroacetic Acid

Dichloroacetic acid was obtained from Aldrich Chemical Co. (Milwaukee, WI) in two lots (05316AR and 11905BU) that were used in the 26- and 39-week dermal studies and the 26- and 41-week drinking water studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle Memorial Institute (Columbus, OH) and the study laboratory at Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the dichloroacetic acid studies are on file at the National Institute of Environmental Health Sciences.

Lots 05316AR (a yellow liquid) and 11905BU (a colorless liquid) were identified as dichloroacetic acid by the analytical chemistry laboratory using infrared spectroscopy (IR) and proton and carbon-13 nuclear magnetic resonance spectroscopy (NMR). Lots 05316AR and 11905BU were identified as dichloroacetic acid by the study laboratory using IR. All IR spectra were consistent with the structure of dichloroacetic acid, with a reference spectrum, and with literature spectra (Aldrich, 1985; Sigma, 1986) of dichloroacetic acid. The NMR spectra were consistent with the structure of dichloroacetic acid and with literature spectra (Aldrich, 1992). IR, proton NMR, and carbon-13 NMR spectra are presented in Figures G1 through G3.

The purity of lot 05316AR was determined by the analytical chemistry laboratory and the study laboratory using high-performance liquid chromatography (HPLC) and by the analytical chemistry laboratory using acid functional group titration. HPLC was performed using a Prodigy 5 ODS-3 column (150 × 4.6 mm, 5 µm particle size; Phenomenex, Torrance, CA) with ultraviolet detection at 220 nm and a mobile phase composed of A) 15 mM phosphoric acid and B) 30 mM phosphoric acid:acetonitrile (1:1); 100% A to 100% B in 20 minutes, 100% B for 15 minutes to 100% A in 5 minutes, and 100% A for 25 minutes at a flow rate of 1.0 mL/minute. Acid functional group titration was performed by titrating a 4 mg/mL solution of dichloroacetic acid in deionized water with certified 0.1003 N sodium hydroxide on a Metrohm 702 SM Titrino automatic titrator with a Metrohm combined pH glass electrode.

For lot 11905BU, moisture content analysis by Karl Fischer titration was performed by Galbraith Laboratories, Inc. (Knoxville, TN). The purity of lot 11905BU was determined by the analytical chemistry laboratory using HPLC by the system described for lot 05316AR, by the analytical chemistry laboratory using acid functional group titration by the method described for lot 05316AR, and by the analytical chemistry laboratory using ion chromatography (IC). IC was performed using an Ionpac AS11 column (250 mm × 4 mm; Dionex, Sunnyvale, CA) with suppressed conductivity detection and a mobile phase composed of A) 4 mM sodium hydroxide and B) 32 mM sodium hydroxide; 100% A for 9.9 minutes to 100% B in 0.1 minute, 100% B for 13.9 minutes to 100% A in 0.1 minutes, and 100% A for 6 minutes at a flow rate of 1.5 mL/minute.

For lot 05316AR, HPLC at the analytical chemistry laboratory indicated one major peak and three impurity peaks with areas less than 1.0% of the major peak area, a combined impurity peak area of 1.20% of the major peak area, and a purity of approximately 98.8%. HPLC at the study laboratory indicated a purity of 99.9% relative to a frozen reference standard of the same lot. Acid functional group titration indicated a purity of approximately 99.4%. The overall purity of lot 05316AR was determined to be greater than 98.5%.

For lot 11905BU, Karl Fischer titration indicated that a minimal amount of water (0.06%) was present. HPLC at the analytical chemistry laboratory indicated one major peak and no impurity peaks greater than or equal to 0.1% of the area of the major peak and a purity of 100%. HPLC at the study laboratory indicated a purity of 100.3%.

Acid functional group titration indicated a purity of approximately 100.6%. IC indicated one major peak and four impurity peaks with combined peak areas of 0.77% of the major peak area. The overall purity of lot 11905BU was determined to be greater than 99%.

Stability studies of a different lot (05703LS) of bulk chemical were performed by the analytical chemistry laboratory using HPLC. HPLC by the system described for purity determination indicated that dichloroacetic acid was stable as a bulk chemical for at least 14 days when stored under a minimal headspace, protected from light in amber glass containers at temperatures up to 60° C. To ensure stability, the bulk chemical was stored at room temperature, protected from light in amber glass containers. Stability was monitored by the study laboratory during the 26-, 39-, and 41-week studies. No degradation of the bulk chemical was detected. Reports on the reanalysis of dichloroacetic acid are on file at the National Institute of Environmental Health Sciences.

### 12-O-tetradecanoylphorbol-13-acetate

12-O-tetradecanoylphorbol-13-acetate (TPA) was obtained from Sigma-Aldrich Chemical Company (St. Louis, MO) in one lot (48H1178) that was used in the 26-week studies in Tg.AC hemizygous mice. Lot 48H1178, a white crystalline powder, was identified as TPA by Research Triangle Institute (RTI; Research Triangle Park, NC) using IR and proton NMR spectroscopy. All spectra were consistent with the structure of TPA.

The purity of lot 48H1178 was determined by RTI using HPLC. HPLC analysis was performed with a Dupont Zorbax Rx C8 column (25 cm × 4.6 mm; Agilent Technologies, Palo Alto, CA), photodiode array detection monitored at 232 nm, and an isocratic mobile phase of water:acetonitrile (10:90) with a flow rate of 1.0 mL/minute. Analysis indicated one major peak and one impurity peak with an area equal to approximately 0.11% of the total integrated peak area. The overall purity of lot 48H1178 was determined to be greater than 99%. The TPA formulations were shown to be stable for at least 6 months.

### Acetone

USP-grade acetone was obtained from Spectrum Chemicals and Laboratory Products (Gardena, CA) in two lots (OG0513 and OX0312) that were used in the 26- and 39-week dermal studies. Lots OG0513 and OX0312, clear liquids, were identified as acetone using IR spectroscopy; the IR spectra were consistent with a literature spectrum.

The purity of lots OG0513 and OX0312 was determined using gas chromatography (GC). The analytical system used a 20% SP-2401/0.1% Carbowax 1500 on 100/120 Supelcoport column (2.4 m × 2 mm; Sigma-Aldrich, St. Louis, MO), a flame ionization detector, helium carrier gas flow rate of approximately 30 mL/minute, and an oven temperature program of 40° C for 4 minutes, then 10° C/minute to 170° C. Analysis indicated one major peak and no impurities with areas greater than or equal to 0.1% of the major peak. The overall purity of both lots was determined to be greater than 99.9%.

## Preparation and Analysis of Dose Formulations

### Dermal Studies

The dose formulations were prepared every 1 to 5 weeks by mixing dichloroacetic acid with deionized water to obtain the required final concentration of dichloroacetic acid (Table G1), adjusting the pH of the solution within a range of six to eight using 20 N sodium hydroxide and 0.1 N hydrochloric acid and adding USP-grade acetone to obtain a water:acetone volume ratio of 1:2. The dose formulations were stored at room temperature in amber glass bottles with Teflon^®^-lined lids and used within 35 days. TPA formulations in acetone were prepared by RTI and administered by the study laboratory.

Stability studies of a 9.5 mg/mL formulation were performed by the study laboratory using GC. The GC system used an RTX-5 column (30 m × 0.53 mm, 1.5 µm film thickness; Restek, Bellefonte, PA), a flame ionization detector, helium carrier gas flowing at approximately 10 mL/minute, and an oven temperature program of 50° C for 1 minute, then 12° C/minute to 150° C, then 70° C/minute to 300° C, and then held for 3 minutes. Stability was confirmed for at least 35 days for dose formulations stored in sealed amber glass containers protected from light at room temperature. Stability of dichloroacetic acid was confirmed in formulations stored open to air and light for at least 3 hours; increases in dichloroacetic acid concentration occurred due to evaporation of acetone.

Periodic analyses of the dose formulations of dichloroacetic acid were conducted by the study laboratory using GC by the system described for formulation stability. During the 26- and 39-week studies, dose formulations were analyzed five times; all 12 of the dose formulations were within 10% of the target concentrations (Table G2). Animal room samples of those dose formulations were also analyzed; five of six animal room samples were within 10% of the target concentrations.

### Drinking Water Studies

Dose formulations were prepared every 1 to 5 weeks by adding a specified amount of dichloroacetic acid to tap water in a calibrated NALGENE^®^ tank to obtain the required concentration (Table G2). The dose formulations were stored at room temperature protected from light in the NALGENE^®^ tanks in which they were prepared with the lids sealed with Parafilm or tape and used within 42 days after formulation. TPA formulations in acetone were prepared by RTI and administered by the study laboratory.

Stability studies of 10 and 100 µg/mL dose formulations were conducted by the analytical chemistry laboratory using an IC system similar to that described for purity determination. Stability was confirmed for at least 42 days for formulations sealed and protected from light in amber glass or NALGENE^®^ containers stored at 5° C and room temperature.

Periodic analyses of the dose formulations of dichloroacetic acid were conducted by the study laboratory using HPLC. HPLC was performed using a Prodigy 5 ODS-3 column (150 mm × 4.6 mm, 5 µm particle size; Phenomenex, Torrance, CA), with ultraviolet detection at 220 nm, and a mobile phase composed of A) 15 mM phosphoric acid and B) 15 mM phosphoric acid:acetonitrile (1:9); 100% A for 13.9 minutes at a flow rate of 1.0 mL/minute, 100% B to 100% A in 0.1 minutes at 1.5 mL/minute, 100% B for 5.9 minutes at 1.5 mL/minute, 100% B to 100% A in 0.1 minutes at 1.0 mL/minute, and 100% A for 5 minutes at 1.0 mL/minute. During the 26- and 41-week studies, dose formulations were analyzed four times; all 12 of the dose formulations for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentrations (Table G3). Animal room samples of those dose formulations were also analyzed; five of six animal room samples for Tg.AC hemizygous mice and all six of the animal room samples for p53 haploinsufficient mice were within 10% of the target concentrations.

FIGURE G1 Infrared Absorption Spectrum of Dichloroacetic Acid

FIGURE G2 Proton Nuclear Magnetic Resonance Spectrum of Dichloroacetic Acid

FIGURE G3 ^13^C-Nuclear Magnetic Resonance Spectrum of Dichloroacetic Acid

TABLE G1 Preparation and Storage of Dose Formulations in the Dermal and Drinking Water Studies of Dichloroacetic Acid

Dermal Studies | Drinking Water Studies
Preparation
Dose formulations were prepared every 1 to 5 weeks by mixing dichloroacetic acid with 1:2 deionized water:USP-grade acetone (Spectrum Chemicals and Laboratory Products, Gardena, CA). | Dose formulations were prepared every 1 to 5 weeks by adding a specified amount of dichloroacetic acid to tap water in a calibrated NALGENE^®^ tank to obtain the required concentration.
12-O-tetradecanoylphorbol-13-acetate formulations were prepared by adding the appropriate amount of 12-O-tetradecanoylphorbol-13-acetate to acetone. | 12-O-tetradecanoylphorbol-13-acetate formulations were prepared by adding the appropriate amount of 12-O-tetradecanoylphorbol-13-acetate to acetone.
Chemical Lot Numbers
05316AR | 05316AR
11905BU | 11905BU
12-O-tetradecanoylphorbol-13-acetate: 48H1178 | 12-O-tetradecanoylphorbol-13-acetate: 48H1178
Maximum Storage Time
35 days | 42 days
12-O-tetradecanoylphorbol-13-acetate: 6 months | 12-O-tetradecanoylphorbol-13-acetate: 6 months
Storage Conditions
Formulations were transferred to 60 mL amber glass bottles, sealed with Teflon^®^-lined lids, protected from light, and stored at room temperature. | Formulations remained in the NALGENE^®^ containers in which they were prepared; the lids were sealed with parafilm or tape, protected from light, and stored at room temperature.
12-O-tetradecanoylphorbol-13-acetate: Stored in amber glass bottles sealed with Teflon^®^-lined lids at 5° C. | 12-O-tetradecanoylphorbol-13-acetate: Stored in amber glass bottles sealed with Teflon^®^-lined lids at 5° C.
Study Laboratory
Battelle Columbus Operations | Battelle Columbus Operations
(Columbus, OH) | (Columbus, OH)

TABLE G2 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice in the 26- and 39-Week Dermal Studies of Dichloroacetic Acid

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
February 2, 2000 | February 7, 2000 | 37.9 | 38.22 | +1
February 2, 2000 | February 7, 2000 | 151.5 | 155.4 | +3
February 2, 2000 | March 15, 2000^b^ | 37.9 | 39.90 | +5
February 2, 2000 | March 15, 2000^b^ | 151.5 | 161.6 | +7
February 9, 2000 | February 9, 2000 | 9.48 | 9.821 | +4
February 9, 2000 | March 15, 2000^b^ | 9.48 | 10.78 | +14
April 19, 2000 | April 20–21, 2000 | 9.48 | 9.891 | +4
April 19, 2000 | April 20–21, 2000 | 37.9 | 35.94 | −5
April 19, 2000 | April 20–21, 2000 | 151.5 | 149.3 | −1
July 10, 2000 | July 12–13, 2000 | 9.48 | 9.402 | −1
July 10, 2000 | July 12–13, 2000 | 37.9 | 37.31 | −2
July 10, 2000 | July 12–13, 2000 | 151.5 | 148.2 | −2
October 4, 2000 | October 4–5, 2000 | 9.48 | 10.24 | +8
October 4, 2000 | October 4–5, 2000 | 37.9 | 37.52 | −1
October 4, 2000 | October 4–5, 2000 | 151.5 | 154.3 | +2
October 4, 2000 | November 9, 2000^b^ | 9.48 | 10.08 | +6
October 4, 2000 | November 9, 2000^b^ | 37.9 | 36.26 | −4
October 4, 2000 | November 9, 2000^b^ | 151.5 | 159.7 | +5

a Results of duplicate analyses. Dosing volume=3.3 mL/kg; 9.48 mg/mL=31.25 mg/kg, 37.9 mg/mL=125 mg/kg, 151.5 mg/mL=500 mg/kg.

b Animal room samples

TABLE G3 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice and p53 Haploinsufficient Mice in the 26- and 41-Week Drinking Water Studies of Dichloroacetic Acid

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
Tg.AC Hemizygous Mice and p53 Haploinsufficient Mice
January 7, 2000 | January 10–11, 2000 | 500 | 506.3 | +1
January 7, 2000 | January 10–11, 2000 | 1,000 | 1092 | +9
January 7, 2000 | January 10–11, 2000 | 2,000 | 2093 | +5
March 27, 2000 | March 28–29, 2000 | 500 | 520.9 | +4
March 27, 2000 | March 28–29, 2000 | 1,000 | 1004 | 0
March 27, 2000 | March 28–29, 2000 | 2,000 | 2037 | +2
June 19, 2000 | June 21–22, 2000 | 500 | 511.0 | +2
June 19, 2000 | June 21–22, 2000 | 1,000 | 1027 | +3
June 19, 2000 | June 21–22, 2000 | 2,000 | 1980 | −1
September 6, 2000 | September 7–8, 2000 | 500 | 507.7 | +2
September 6, 2000 | September 7–8, 2000 | 1,000 | 1030 | +3
September 6, 2000 | September 7–8, 2000 | 2,000 | 2125 | +6
Animal Room Samples
Tg.AC Hemizygous Mice
January 7, 2000 | February 15–16, 2000 | 500 | 524.2 | +5
January 7, 2000 | February 15–16, 2000 | 1,000 | 1067 | +7
January 7, 2000 | February 15–16, 2000 | 2,000 | 2241 | +12
September 6, 2000 | October 18–19, 2000 | 500 | 512.2 | +2
September 6, 2000 | October 18–19, 2000 | 1,000 | 1034 | +3
September 6, 2000 | October 18–19, 2000 | 2,000 | 2077 | +4
p53 Haploinsufficient Mice
January 7, 2000 | February 15–16, 2000 | 500 | 524.3 | +5
January 7, 2000 | February 15–16, 2000 | 1,000 | 1068 | +7
January 7, 2000 | February 15–16, 2000 | 2,000 | 2140 | +7
September 6, 2000 | October 18–19, 2000 | 500 | 508.8 | +2
September 6, 2000 | October 18–19, 2000 | 1,000 | 1022 | +2
September 6, 2000 | October 18–19, 2000 | 2,000 | 1983 | −1

a Results of duplicate analyses