# APPENDIX F ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE F1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
n | 13 | 14 | 14 | 12
Necropsy body wt | 33.6 ± 0.9 | 33.3 ± 0.6 | 33.6 ± 0.8 | 33.3 ± 1.2
Heart
Absolute | 0.176 ± 0.005 | 0.175 ± 0.003 | 0.182 ± 0.007 | 0.175 ± 0.006
Relative | 5.242 ± 0.112 | 5.269 ± 0.093 | 5.421 ± 0.183 | 5.265 ± 0.123
R. Kidney
Absolute | 0.299 ± 0.007^b^ | 0.308 ± 0.007 | 0.315 ± 0.008 | 0.300 ± 0.010
Relative | 8.911 ± 0.236^b^ | 9.280 ± 0.230 | 9.429 ± 0.282 | 9.064 ± 0.322
Liver
Absolute | 1.586 ± 0.046 | 1.580 ± 0.030 | 1.856 ± 0.061^**^ | 2.642 ± 0.103^**^
Relative | 47.221 ± 0.601 | 47.558 ± 0.667 | 55.113 ± 0.998^**^ | 79.321 ± 1.631^**^
Lung
Absolute | 0.279 ± 0.013 | 0.268 ± 0.012 | 0.278 ± 0.013 | 0.266 ± 0.015
Relative | 8.298 ± 0.272 | 8.080 ± 0.366 | 8.309 ± 0.385 | 8.105 ± 0.527
R. Testis
Absolute | 0.086 ± 0.004 | 0.086 ± 0.003 | 0.092 ± 0.003 | 0.081 ± 0.002
Relative | 2.563 ± 0.113 | 2.591 ± 0.076 | 2.743 ± 0.100 | 2.471 ± 0.102
Thymus
Absolute | 0.030 ± 0.002 | 0.033 ± 0.002 | 0.028 ± 0.002 | 0.029 ± 0.003
Relative | 0.906 ± 0.068 | 0.998 ± 0.044 | 0.835 ± 0.051 | 0.842 ± 0.083
Female
n | 11 | 12 | 14 | 15
Necropsy body wt | 25.4 ± 1.3 | 27.3 ± 1.0 | 27.5 ± 1.4 | 27.0 ± 0.5
Heart
Absolute | 0.139 ± 0.006 | 0.135 ± 0.002 | 0.150 ± 0.004 | 0.144 ± 0.004
Relative | 5.531 ± 0.178 | 5.012 ± 0.146^*^ | 5.521 ± 0.141 | 5.323 ± 0.107
R. Kidney
Absolute | 0.208 ± 0.007 | 0.207 ± 0.004 | 0.207 ± 0.005 | 0.206 ± 0.006
Relative | 8.284 ± 0.268 | 7.674 ± 0.207 | 7.661 ± 0.250 | 7.658 ± 0.269
Liver
Absolute | 1.344 ± 0.073 | 1.346 ± 0.041 | 1.516 ± 0.056^*^ | 2.241 ± 0.042^**^
Relative | 52.997 ± 1.477 | 49.543 ± 0.645 | 55.501 ± 1.165 | 83.136 ± 1.130^**^
Lung
Absolute | 0.237 ± 0.014^c^ | 0.265 ± 0.014 | 0.278 ± 0.012 | 0.241 ± 0.011
Relative | 9.634 ± 0.684^c^ | 9.845 ± 0.595 | 10.206 ± 0.416 | 8.931 ± 0.405
Thymus
Absolute | 0.028 ± 0.003 | 0.034 ± 0.002 | 0.031 ± 0.002 | 0.032 ± 0.001
Relative | 1.096 ± 0.067 | 1.229 ± 0.062 | 1.137 ± 0.066 | 1.175 ± 0.045

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights are given as mg organ weight/g body weight (mean ± standard error).

b n=12

c n=10

TABLE F2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
n | 9 | 6 | 8 | 7
Necropsy body wt | 37.2 ± 1.5 | 34.0 ± 0.8 | 36.7 ± 1.1 | 34.0 ± 1.1
Heart
Absolute | 0.199 ± 0.007 | 0.225 ± 0.004 | 0.199 ± 0.009 | 0.187 ± 0.008
Relative | 5.413 ± 0.266 | 6.640 ± 0.167^**^ | 5.411 ± 0.214 | 5.518 ± 0.191
R. Kidney
Absolute | 0.392 ± 0.023 | 0.329 ± 0.006^*^ | 0.350 ± 0.010 | 0.354 ± 0.013
Relative | 10.652 ± 0.752 | 9.698 ± 0.177 | 9.562 ± 0.302 | 10.431 ± 0.237
Liver
Absolute | 1.985 ± 0.072 | 1.907 ± 0.048 | 2.311 ± 0.062^**^ | 3.169 ± 0.130^**^
Relative | 53.630 ± 1.356 | 56.197 ± 1.729 | 63.108 ± 1.597^**^ | 93.239 ± 1.904^**^
Lung
Absolute | 0.243 ± 0.013 | 0.306 ± 0.029 | 0.270 ± 0.023^b^ | 0.256 ± 0.024
Relative | 6.625 ± 0.450 | 8.987 ± 0.865^*^ | 7.428 ± 0.688^b^ | 7.504 ± 0.615
R. Testis
Absolute | 0.084 ± 0.005 | 0.088 ± 0.003 | 0.087 ± 0.004 | 0.070 ± 0.002
Relative | 2.278 ± 0.153 | 2.579 ± 0.101 | 2.378 ± 0.140 | 2.071 ± 0.092
Thymus
Absolute | 0.032 ± 0.003 | 0.032 ± 0.003 | 0.027 ± 0.002 | 0.020 ± 0.003^**^
Relative | 0.856 ± 0.079 | 0.929 ± 0.075 | 0.738 ± 0.064 | 0.581 ± 0.077^*^
Female
n | 8 | 5 | 6 | 8
Necropsy body wt | 27.3 ± 0.9 | 28.8 ± 1.6 | 29.9 ± 1.3^b^ | 35.4 ± 3.6^*^
Heart
Absolute | 0.166 ± 0.012 | 0.154 ± 0.009 | 0.156 ± 0.009 | 0.157 ± 0.008
Relative | 6.048 ± 0.318 | 5.403 ± 0.441 | 5.427 ± 0.322 | 4.595 ± 0.248^**^
R. Kidney
Absolute | 0.238 ± 0.004 | 0.226 ± 0.011 | 0.233 ± 0.012 | 0.261 ± 0.018
Relative | 8.756 ± 0.285 | 7.865 ± 0.343 | 8.091 ± 0.293 | 7.749 ± 0.674
Liver
Absolute | 1.615 ± 0.044 | 1.637 ± 0.109 | 1.916 ± 0.117 | 3.015 ± 0.158^**^
Relative | 59.456 ± 1.946 | 56.900 ± 2.579 | 66.450 ± 3.486 | 88.320 ± 4.861^**^
Lung
Absolute | 0.245 ± 0.023 | 0.236 ± 0.019 | 0.233 ± 0.019 | 0.227 ± 0.017
Relative | 8.988 ± 0.774 | 8.413 ± 1.087 | 8.120 ± 0.683 | 6.670 ± 0.583
Thymus
Absolute | 0.020 ± 0.002 | 0.026 ± 0.001 | 0.031 ± 0.002^*^ | 0.034 ± 0.005^**^
Relative | 0.744 ± 0.078 | 0.918 ± 0.063 | 1.065 ± 0.063^*^ | 0.963 ± 0.106

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights are given as mg organ weight/g body weight (mean ± standard error).

b n=7

TABLE F3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 14 | 13 | 11 | 14
Necropsy body wt | 34.5 ± 0.8 | 35.6 ± 1.9 | 35.9 ± 1.3 | 34.1 ± 0.7
Heart
Absolute | 0.187 ± 0.004 | 0.185 ± 0.008 | 0.179 ± 0.010 | 0.173 ± 0.005
Relative | 5.451 ± 0.169 | 5.249 ± 0.155 | 5.059 ± 0.370 | 5.078 ± 0.147
R. Kidney
Absolute | 0.301 ± 0.006 | 0.310 ± 0.013 | 0.325 ± 0.010 | 0.337 ± 0.015
Relative | 8.756 ± 0.159 | 8.811 ± 0.200 | 9.091 ± 0.210 | 9.871 ± 0.355^**^
Liver
Absolute | 1.710 ± 0.056 | 1.976 ± 0.103^*^ | 2.301 ± 0.101^**^ | 2.626 ± 0.074^**^
Relative | 49.511 ± 0.863 | 55.690 ± 1.082^**^ | 64.184 ± 1.846^**^ | 76.971 ± 1.640^**^
Lung
Absolute | 0.282 ± 0.014 | 0.306 ± 0.015 | 0.304 ± 0.016 | 0.330 ± 0.010^*^
Relative | 8.173 ± 0.364 | 8.806 ± 0.539 | 8.473 ± 0.359 | 9.624 ± 0.304^*^
R. Testis
Absolute | 0.086 ± 0.003 | 0.087 ± 0.004 | 0.090 ± 0.002 | 0.086 ± 0.002
Relative | 2.516 ± 0.104 | 2.458 ± 0.077 | 2.517 ± 0.067 | 2.526 ± 0.096
Thymus
Absolute | 0.028 ± 0.002 | 0.033 ± 0.003 | 0.034 ± 0.003 | 0.031 ± 0.002
Relative | 0.803 ± 0.061 | 0.901 ± 0.061 | 0.961 ± 0.065 | 0.896 ± 0.038
Female
n | 15 | 8 | 13 | 10
Necropsy body wt | 31.2 ± 1.2 | 33.3 ± 2.5 | 29.0 ± 1.3 | 28.2 ± 0.7
Heart
Absolute | 0.149 ± 0.003 | 0.156 ± 0.005 | 0.145 ± 0.005 | 0.141 ± 0.005
Relative | 4.839 ± 0.152 | 4.797 ± 0.207 | 5.048 ± 0.169 | 5.018 ± 0.148
R. Kidney
Absolute | 0.216 ± 0.005 | 0.220 ± 0.006 | 0.214 ± 0.008 | 0.210 ± 0.004
Relative | 7.042 ± 0.223 | 6.834 ± 0.490 | 7.434 ± 0.201 | 7.460 ± 0.225
Liver
Absolute | 1.481 ± 0.058^b^ | 1.950 ± 0.070^**^ | 1.968 ± 0.095^**^ | 2.230 ± 0.067^**^
Relative | 47.883 ± 1.262^b^ | 59.781 ± 2.514^**^ | 68.018 ± 1.795^**^ | 79.151 ± 2.192^**^
Lung
Absolute | 0.259 ± 0.011 | 0.271 ± 0.020 | 0.282 ± 0.014 | 0.290 ± 0.015
Relative | 8.377 ± 0.363 | 8.202 ± 0.466 | 9.846 ± 0.492^*^ | 10.279 ± 0.446^**^
Thymus
Absolute | 0.033 ± 0.003 | 0.041 ± 0.006 | 0.032 ± 0.003 | 0.033 ± 0.002
Relative | 1.092 ± 0.098 | 1.209 ± 0.099 | 1.098 ± 0.081 | 1.171 ± 0.070

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights are given as mg organ weight/g body weight (mean ± standard error).

b n=14

TABLE F4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 9 | 9 | 10 | 10
Necropsy body wt | 40.6 ± 2.0 | 38.0 ± 1.6 | 36.7 ± 1.4 | 34.9 ± 0.7^*^
Heart
Absolute | 0.199 ± 0.007 | 0.193 ± 0.006 | 0.183 ± 0.008 | 0.168 ± 0.003^**^
Relative | 4.942 ± 0.176 | 5.119 ± 0.202 | 4.988 ± 0.103 | 4.837 ± 0.106
R. Kidney
Absolute | 0.374 ± 0.015 | 0.356 ± 0.014 | 0.350 ± 0.021 | 0.341 ± 0.011
Relative | 9.269 ± 0.252 | 9.471 ± 0.496 | 9.500 ± 0.392 | 9.774 ± 0.283
Liver
Absolute | 2.068 ± 0.122 | 2.341 ± 0.064 | 2.613 ± 0.094^**^,^b^ | 2.662 ± 0.118^**^
Relative | 50.750 ± 1.264 | 62.467 ± 3.023^**^ | 69.852 ± 1.090^**^,^b^ | 76.306 ± 2.859^**^
Lung
Absolute | 0.225 ± 0.013 | 0.234 ± 0.016 | 0.218 ± 0.007 | 0.229 ± 0.015
Relative | 5.649 ± 0.409 | 6.214 ± 0.477 | 5.987 ± 0.207 | 6.579 ± 0.430
R. Testis
Absolute | 0.090 ± 0.001 | 0.090 ± 0.002 | 0.086 ± 0.001 | 0.075 ± 0.006^**^
Relative | 2.275 ± 0.135 | 2.395 ± 0.095 | 2.377 ± 0.092 | 2.168 ± 0.170
Thymus
Absolute | 0.043 ± 0.005 | 0.032 ± 0.003 | 0.032 ± 0.005 | 0.022 ± 0.002^**^
Relative | 1.040 ± 0.093 | 0.867 ± 0.112 | 0.843 ± 0.112 | 0.616 ± 0.062^**^
Female
n | 7 | 9 | 7 | 8
Necropsy body wt | 34.2 ± 1.1 | 34.2 ± 2.3 | 30.9 ± 1.2 | 28.2 ± 1.7^*^
Heart
Absolute | 0.162 ± 0.004 | 0.152 ± 0.007 | 0.146 ± 0.003 | 0.134 ± 0.004^**^
Relative | 4.748 ± 0.105 | 4.510 ± 0.214 | 4.770 ± 0.165 | 4.823 ± 0.240
R. Kidney
Absolute | 0.249 ± 0.009 | 0.237 ± 0.004 | 0.239 ± 0.007 | 0.225 ± 0.010
Relative | 7.311 ± 0.203 | 7.104 ± 0.350 | 7.767 ± 0.241 | 8.090 ± 0.397
Liver
Absolute | 1.815 ± 0.067 | 2.115 ± 0.093 | 2.237 ± 0.058^*^ | 2.172 ± 0.120^*^
Relative | 53.126 ± 0.667 | 63.379 ± 4.158^*^ | 72.912 ± 2.566^**^ | 77.593 ± 3.227^**^
Lung
Absolute | 0.205 ± 0.007 | 0.203 ± 0.010 | 0.194 ± 0.008 | 0.232 ± 0.013
Relative | 5.999 ± 0.156 | 6.156 ± 0.513 | 6.324 ± 0.342 | 8.433 ± 0.648^**^
Thymus
Absolute | 0.033 ± 0.003 | 0.030 ± 0.001 | 0.030 ± 0.001 | 0.028 ± 0.003
Relative | 0.974 ± 0.070 | 0.898 ± 0.045 | 0.980 ± 0.029 | 0.998 ± 0.072

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights are given as mg organ weight/g body weight (mean ± standard error).

b n=9

TABLE F5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 15 | 15 | 15 | 15
Necropsy body wt | 47.4 ± 0.8 | 45.5 ± 1.3 | 37.0 ± 1.5^**^ | 32.9 ± 0.9^**^
Heart
Absolute | 0.213 ± 0.007 | 0.202 ± 0.007 | 0.177 ± 0.004^**^ | 0.172 ± 0.005
Relative | 4.501 ± 0.128 | 4.446 ± 0.131 | 4.849 ± 0.147 | 5.232 ± 0.125^**^
R. Kidney
Absolute | 0.307 ± 0.009 | 0.285 ± 0.008 | 0.265 ± 0.010^**^ | 0.261 ± 0.005^**^
Relative | 6.494 ± 0.209 | 6.328 ± 0.246 | 7.235 ± 0.206^*^ | 7.974 ± 0.210^**^
Liver
Absolute | 2.716 ± 0.138 | 2.725 ± 0.176 | 2.345 ± 0.124 | 2.655 ± 0.078
Relative | 56.925 ± 2.138 | 59.197 ± 2.182 | 63.235 ± 1.176^*^ | 80.726 ± 1.092^**^
Lung
Absolute | 0.284 ± 0.009 | 0.267 ± 0.017 | 0.278 ± 0.009 | 0.280 ± 0.012
Relative | 6.031 ± 0.230 | 5.924 ± 0.427 | 7.719 ± 0.404^**^ | 8.610 ± 0.481^**^
R. Testis
Absolute | 0.110 ± 0.002 | 0.111 ± 0.003 | 0.105 ± 0.002 | 0.105 ± 0.002
Relative | 2.338 ± 0.061 | 2.459 ± 0.069 | 2.893 ± 0.110^**^ | 3.230 ± 0.113^**^
Thymus
Absolute | 0.057 ± 0.003 | 0.055 ± 0.006 | 0.048 ± 0.002 | 0.043 ± 0.002^*^
Relative | 1.195 ± 0.052 | 1.199 ± 0.126 | 1.310 ± 0.058 | 1.318 ± 0.046
Female
n | 15 | 15 | 14 | 14
Necropsy body wt | 31.4 ± 1.4 | 28.8 ± 1.0 | 25.3 ± 0.5^**^ | 25.0 ± 0.4^**^
Heart
Absolute | 0.157 ± 0.003 | 0.153 ± 0.004 | 0.151 ± 0.003 | 0.139 ± 0.003^**^
Relative | 5.105 ± 0.203 | 5.351 ± 0.111 | 5.986 ± 0.142^**^ | 5.563 ± 0.090
R. Kidney
Absolute | 0.199 ± 0.004 | 0.193 ± 0.004 | 0.188 ± 0.004 | 0.183 ± 0.004^**^
Relative | 6.466 ± 0.222 | 6.749 ± 0.135 | 7.450 ± 0.141^**^ | 7.341 ± 0.089^**^
Liver
Absolute | 1.443 ± 0.044 | 1.721 ± 0.065^**^ | 1.782 ± 0.041^**^ | 2.064 ± 0.045^**^
Relative | 46.438 ± 0.953 | 59.841 ± 1.158^**^ | 70.375 ± 0.862^**^ | 82.671 ± 1.175^**^
Lung
Absolute | 0.274 ± 0.012 | 0.281 ± 0.012 | 0.265 ± 0.013 | 0.251 ± 0.008
Relative | 8.960 ± 0.524 | 9.931 ± 0.521 | 10.451 ± 0.474 | 10.069 ± 0.365
Thymus
Absolute | 0.058 ± 0.002 | 0.056 ± 0.002 | 0.054 ± 0.002 | 0.051 ± 0.002
Relative | 1.882 ± 0.100 | 1.941 ± 0.073 | 2.125 ± 0.087 | 2.041 ± 0.060

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights are given as mg organ weight/g body weight (mean ± standard error).

TABLE F6 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 9 | 10 | 9 | 10
Necropsy body wt | 52.3 ± 1.2 | 46.8 ± 1.7^*^ | 35.7 ± 1.2^**^ | 35.8 ± 2.0^**^
Heart
Absolute | 0.263 ± 0.016 | 0.232 ± 0.011 | 0.220 ± 0.016^*^ | 0.181 ± 0.008^**^
Relative | 5.006 ± 0.235 | 4.977 ± 0.198 | 6.165 ± 0.409^*^ | 5.150 ± 0.302
R. Kidney
Absolute | 0.376 ± 0.016 | 0.332 ± 0.014^*^ | 0.307 ± 0.008^**^ | 0.271 ± 0.011^**^
Relative | 7.196 ± 0.271 | 7.125 ± 0.248 | 8.676 ± 0.343^**^ | 7.657 ± 0.186
Liver
Absolute | 3.656 ± 0.108 | 3.274 ± 0.286 | 2.458 ± 0.060^**^ | 2.981 ± 0.144^**^
Relative | 69.979 ± 1.672 | 68.937 ± 3.757 | 69.101 ± 1.300 | 83.735 ± 1.834^**^
Lung
Absolute | 0.231 ± 0.009 | 0.240 ± 0.016 | 0.243 ± 0.030 | 0.235 ± 0.016
Relative | 4.418 ± 0.156 | 5.183 ± 0.356 | 6.811 ± 0.832^**^ | 6.743 ± 0.593^**^
R. Testis
Absolute | 0.112 ± 0.003 | 0.108 ± 0.002 | 0.102 ± 0.002^**^ | 0.102 ± 0.003^**^,^b^
Relative | 2.149 ± 0.051 | 2.339 ± 0.107 | 2.898 ± 0.122^**^ | 2.855 ± 0.149^**^,^b^
Thymus
Absolute | 0.071 ± 0.005 | 0.114 ± 0.056 | 0.040 ± 0.004 | 0.044 ± 0.003
Relative | 1.351 ± 0.094 | 2.381 ± 1.145 | 1.103 ± 0.102 | 1.229 ± 0.054
Female
n | 10 | 9 | 10 | 9
Necropsy body wt | 43.7 ± 2.5 | 37.7 ± 2.8^*^ | 28.2 ± 0.9^**^ | 26.9 ± 0.7^**^
Heart
Absolute | 0.179 ± 0.004 | 0.178 ± 0.004 | 0.153 ± 0.004^**^ | 0.150 ± 0.006^**^
Relative | 4.185 ± 0.204 | 4.899 ± 0.332^*^ | 5.450 ± 0.142^**^ | 5.589 ± 0.187^**^
R. Kidney
Absolute | 0.235 ± 0.005 | 0.234 ± 0.005 | 0.207 ± 0.004^**^ | 0.189 ± 0.005^**^
Relative | 5.505 ± 0.248 | 6.431 ± 0.378^*^ | 7.387 ± 0.237^**^ | 7.035 ± 0.219^**^
Liver
Absolute | 1.854 ± 0.088 | 2.089 ± 0.091^*^ | 2.160 ± 0.078^**^ | 2.390 ± 0.055^**^
Relative | 42.847 ± 1.448 | 56.776 ± 2.618^**^ | 76.712 ± 1.960^**^ | 88.810 ± 0.984^**^
Lung
Absolute | 0.224 ± 0.008 | 0.202 ± 0.007 | 0.206 ± 0.014 | 0.241 ± 0.023
Relative | 5.203 ± 0.209 | 5.580 ± 0.405 | 7.315 ± 0.414^**^ | 8.917 ± 0.724^**^
Thymus
Absolute | 0.052 ± 0.003 | 0.050 ± 0.003 | 0.052 ± 0.004 | 0.047 ± 0.003
Relative | 1.200 ± 0.052 | 1.373 ± 0.095 | 1.847 ± 0.117^**^ | 1.741 ± 0.117^**^

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights are given as mg organ weight/g body weight (mean ± standard error).

b n=9