# APPENDIX E HEMATOLOGY RESULTS

TABLE E1 Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Male
n | 13 | 14 | 14 | 11
Hematocrit (%) | 41.8 ± 0.5 | 42.4 ± 0.6 | 41.3 ± 0.6 | 40.9 ± 0.5
Hemoglobin (g/dL) | 13.8 ± 0.2 | 13.9 ± 0.2 | 13.6 ± 0.2 | 13.3 ± 0.2
Erythrocytes (10^6^/µL) | 9.63 ± 0.15 | 9.77 ± 0.17 | 9.41 ± 0.16 | 9.50 ± 0.16
Reticulocytes (10^6^/µL) | 0.11 ± 0.01 | 0.12 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.02
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 43.4 ± 0.3 | 43.4 ± 0.3 | 43.9 ± 0.3 | 43.1 ± 0.4
Mean cell hemoglobin (pg) | 14.3 ± 0.1 | 14.3 ± 0.1 | 14.5 ± 0.1 | 14.0 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 33.0 ± 0.1 | 32.8 ± 0.1 | 32.9 ± 0.2 | 32.4 ± 0.1^*^
Platelets (10^3^/µL) | 975.3 ± 18.5 | 1,010.4 ± 20.2 | 1,050.7 ± 36.9^*^ | 1,058.3 ± 22.5^**^
Leukocytes (10^3^/µL) | 3.08 ± 0.19 | 2.94 ± 0.33 | 2.32 ± 0.21 | 3.17 ± 0.44
Segmented neutrophils (10^3^/µL) | 0.44 ± 0.05 | 0.40 ± 0.08 | 0.36 ± 0.06 | 0.71 ± 0.21
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.61 ± 0.16 | 2.50 ± 0.25 | 1.93 ± 0.16 | 2.43 ± 0.37
Monocytes (10^3^/µL) | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.01 ± 0.01 | 0.03 ± 0.01
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.01 ± 0.01
Female
n | 10 | 12 | 14 | 13
Hematocrit (%) | 43.2 ± 0.7 | 44.4 ± 0.5 | 44.0 ± 0.6 | 42.4 ± 0.4
Hemoglobin (g/dL) | 14.2 ± 0.2 | 14.7 ± 0.2 | 14.4 ± 0.2 | 13.9 ± 0.1
Erythrocytes (10^6^/µL) | 9.64 ± 0.19 | 9.94 ± 0.21 | 9.81 ± 0.14 | 9.58 ± 0.12
Reticulocytes (10^6^/µL) | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.16 ± 0.01 | 0.13 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.9 ± 0.5 | 44.7 ± 0.4 | 44.9 ± 0.2 | 44.3 ± 0.2
Mean cell hemoglobin (pg) | 14.8 ± 0.2 | 14.8 ± 0.2 | 14.7 ± 0.1 | 14.5 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.0 ± 0.1 | 33.2 ± 0.2 | 32.7 ± 0.1 | 32.8 ± 0.1
Platelets (10^3^/µL) | 893.3 ± 75.2 | 770.0 ± 25.8 | 874.9 ± 40.3 | 927.6 ± 32.8
Leukocytes (10^3^/µL) | 3.94 ± 0.41 | 2.97 ± 0.18 | 3.74 ± 0.31 | 4.22 ± 0.22
Segmented neutrophils (10^3^/µL) | 1.15 ± 0.43 | 0.28 ± 0.05^*^ | 0.57 ± 0.14 | 0.47 ± 0.07
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.71 ± 0.26 | 2.64 ± 0.13 | 3.13 ± 0.22 | 3.66 ± 0.19^**^
Monocytes (10^3^/µL) | 0.07 ± 0.02 | 0.05 ± 0.02 | 0.04 ± 0.01 | 0.07 ± 0.03
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.02 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE E2 Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 14 | 13 | 11 | 14
Hematocrit (%) | 42.4 ± 0.3 | 43.1 ± 0.7 | 43.5 ± 0.8 | 44.3 ± 0.5^*^
Hemoglobin (g/dL) | 14.1 ± 0.1 | 14.4 ± 0.2 | 14.5 ± 0.3 | 14.6 ± 0.2
Erythrocytes (10^6^/µL) | 9.82 ± 0.08 | 10.29 ± 0.29 | 10.35 ± 0.30 | 10.33 ± 0.15
Reticulocytes (10^6^/µL) | 0.17 ± 0.01 | 0.18 ± 0.02 | 0.15 ± 0.01 | 0.14 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 43.2 ± 0.1 | 42.1 ± 0.6 | 42.2 ± 0.7 | 42.9 ± 0.2
Mean cell hemoglobin (pg) | 14.4 ± 0.1 | 14.1 ± 0.2 | 14.1 ± 0.3 | 14.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.3 ± 0.1 | 33.4 ± 0.2 | 33.4 ± 0.3 | 33.0 ± 0.1
Platelets (10^3^/µL) | 1,119.8 ± 18.5 | 1,326.5 ± 83.4 | 1,201.4 ± 76.8 | 1,112.0 ± 25.9
Leukocytes (10^3^/µL) | 3.14 ± 0.19 | 4.60 ± 0.52 | 4.85 ± 0.45^**^ | 3.56 ± 0.38
Segmented neutrophils (10^3^/µL) | 0.59 ± 0.07 | 1.52 ± 0.43^*^ | 1.26 ± 0.18^**^ | 0.66 ± 0.10
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.54 ± 0.18 | 3.03 ± 0.13 | 3.55 ± 0.28^*^ | 2.88 ± 0.31
Monocytes (10^3^/µL) | 0.00 ± 0.00 | 0.02 ± 0.02 | 0.01 ± 0.01 | 0.00 ± 0.00
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01
Female
n | 13 | 8 | 13 | 10
Hematocrit (%) | 43.5 ± 0.5 | 44.1 ± 0.4 | 43.7 ± 0.3 | 44.1 ± 0.9
Hemoglobin (g/dL) | 14.4 ± 0.1 | 14.5 ± 0.1 | 14.4 ± 0.1 | 14.6 ± 0.3
Erythrocytes (10^6^/µL) | 9.70 ± 0.15 | 10.13 ± 0.19 | 9.71 ± 0.15 | 10.07 ± 0.29
Reticulocytes (10^6^/µL) | 0.14 ± 0.01 | 0.16 ± 0.02 | 0.15 ± 0.02 | 0.14 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.9 ± 0.3 | 43.6 ± 0.8 | 45.1 ± 0.4 | 43.9 ± 0.6
Mean cell hemoglobin (pg) | 14.9 ± 0.1 | 14.4 ± 0.3 | 14.9 ± 0.2 | 14.6 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 33.1 ± 0.1 | 33.0 ± 0.1 | 33.0 ± 0.1 | 33.2 ± 0.1
Platelets (10^3^/µL) | 917.0 ± 25.9 | 1,071.8 ± 93.3 | 904.7 ± 40.9 | 881.3 ± 30.4
Leukocytes (10^3^/µL) | 3.97 ± 0.22 | 4.59 ± 0.35 | 4.15 ± 0.25 | 4.28 ± 0.42
Segmented neutrophils (10^3^/µL) | 0.57 ± 0.07 | 0.79 ± 0.14 | 0.63 ± 0.09 | 0.68 ± 0.12
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 3.39 ± 0.17 | 3.76 ± 0.26 | 3.50 ± 0.19 | 3.57 ± 0.36
Monocytes (10^3^/µL) | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01

* Significantly different (P≤0.05) from the control group by Dunn’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE E3 Hematology Data for p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 15 | 15 | 15 | 15
Hematocrit (%) | 47.7 ± 0.5 | 47.2 ± 0.4 | 46.8 ± 0.4 | 47.3 ± 0.5
Hemoglobin (g/dL) | 15.6 ± 0.2 | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.5 ± 0.2
Erythrocytes (10^6^/µL) | 10.70 ± 0.13 | 10.73 ± 0.10 | 10.71 ± 0.09 | 10.84 ± 0.15
Reticulocytes (10^6^/µL) | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.6 ± 0.2 | 44.0 ± 0.2^*^ | 43.6 ± 0.2^**^ | 43.6 ± 0.2^**^
Mean cell hemoglobin (pg) | 14.6 ± 0.1 | 14.5 ± 0.1 | 14.4 ± 0.0 | 14.3 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.7 ± 0.1 | 33.0 ± 0.1 | 33.1 ± 0.1^*^ | 32.8 ± 0.1
Platelets (10^3^/µL) | 939.4 ± 25.8 | 970.5 ± 24.8 | 1,122.7 ± 75.0^**^ | 1,074.8 ± 48.3^**^
Leukocytes (10^3^/µL) | 6.28 ± 0.40 | 5.75 ± 0.34 | 6.43 ± 0.39 | 6.12 ± 0.52
Segmented neutrophils (10^3^/µL) | 0.88 ± 0.08 | 0.73 ± 0.06 | 1.09 ± 0.14 | 1.01 ± 0.14
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 5.34 ± 0.33 | 4.96 ± 0.29 | 5.26 ± 0.33 | 5.03 ± 0.39
Monocytes (10^3^/µL) | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.02 | 0.05 ± 0.02
Female
n | 15 | 15 | 14 | 14
Hematocrit (%) | 45.6 ± 0.4 | 45.9 ± 0.5 | 45.5 ± 0.3 | 45.0 ± 0.4
Hemoglobin (g/dL) | 15.2 ± 0.1 | 15.2 ± 0.2 | 15.2 ± 0.1 | 15.0 ± 0.1
Erythrocytes (10^6^/µL) | 10.31 ± 0.12 | 10.35 ± 0.14 | 10.35 ± 0.07 | 10.51 ± 0.09
Reticulocytes (10^6^/µL) | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.13 ± 0.01 | 0.15 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.3 ± 0.2 | 44.3 ± 0.2 | 44.0 ± 0.2 | 42.8 ± 0.2^**^
Mean cell hemoglobin (pg) | 14.8 ± 0.1 | 14.7 ± 0.1 | 14.6 ± 0.1 | 14.3 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 33.3 ± 0.1 | 33.1 ± 0.1 | 33.3 ± 0.2 | 33.4 ± 0.2
Platelets (10^3^/µL) | 831.9 ± 20.9 | 871.4 ± 48.6 | 964.4 ± 43.6^*^ | 867.1 ± 37.6
Leukocytes (10^3^/µL) | 2.91 ± 0.17 | 3.55 ± 0.37 | 3.03 ± 0.20 | 4.33 ± 0.28^**^
Segmented neutrophils (10^3^/µL) | 0.32 ± 0.02 | 0.51 ± 0.25 | 0.49 ± 0.06^*^ | 0.75 ± 0.08^**^
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.55 ± 0.16 | 3.00 ± 0.27 | 2.47 ± 0.17 | 3.50 ± 0.21^*^
Monocytes (10^3^/µL) | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.05 ± 0.02

* Significantly different (P≤0.05) from the control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.