# APPENDIX D GENETIC TOXICOLOGY

TABLE D1 Mutagenicity of Dichloroacetic Acid in Salmonella typhimurium^a^

Strain | Dose (µg/plate) | Revertants/Plate^b^
Strain | Dose (µg/plate) | −S9 | | | +30% hamster S9 | +30% rat S9
Strain | Dose (µg/plate) | Trial 1 | Trial 2 | Trial 3 | +30% hamster S9 | +30% rat S9
TA100 ^c^ | 0 | 129 ± 2.9 | 97 ± 8.8 | 109 ± 13.4 | 121 ± 8.6 | 156 ± 4.3
| 33 | 134 ± 7.2 | | | 124 ± 10.2 | 147 ± 3.2
| 100 | 131 ± 11.7 | 104 ± 10.4 | | 135 ± 5.8 | 162 ± 5.0
| 333 | 153 ± 0.7 | 111 ± 7.4 | 96 ± 1.9 | 140 ± 6.4 | 167 ± 5.0
| 666 | | 120 ± 3.3 | 146 ± 13.9
| 1,000 | 188 ± 1.5 | 129 ± 9.3 | 157 ± 11.2 | 133 ± 11.4 | 175 ± 0.9
| 1,666 | | 170 ± 4.4 | 158 ± 6.0
| 3,333 | 307 ± 14.6 | 186 ± 4.6 | 238 ± 4.0 | 135 ± 3.5 | 160 ± 2.5
| 6,666 | | | Toxic
Trial summary | | Positive | Positive | Positive | Negative | Negative
Positive control^d^ | | 734 ± 20.6 | 590 ± 24.4 | 309 ± 18.9 | 542 ± 22.7 | 373 ± 1.2
TA100 ^e^ | 0 | 132 ± 3.3 | 105 ± 12.0 | | 142 ± 15.4 | 149 ± 1.7
| 33 | 113 ± 13.0 | | | 153 ± 3.8 | 143 ± 4.8
| 100 | 128 ± 5.0 | | | 161 ± 1.8 | 164 ± 11.7
| 333 | 135 ± 9.0 | 113 ± 8.3 | | 133 ± 3.8 | 148 ± 7.0
| 666 | | 131 ± 5.2
| 1,000 | 180 ± 3.2 | 158 ± 5.5 | | 145 ± 9.9 | 148 ± 3.8
| 1,666 | | 194 ± 5.0
| 3,333 | 442 ± 19.6 | 315 ± 30.7 | | 139 ± 2.2 | 137 ± 3.0
| 6,666 | | Toxic
Trial summary | | Positive | Positive | | Negative | Negative
Positive control | | 951 ± 25.6 | 919 ± 17.2 | | 1,022 ± 22.5 | 629 ± 50.7
TA1535 ^c^ | 0 | 12 ± 2.0 | 9 ± 1.7 | 9 ± 0.6
| 333 | 14 ± 1.7
| 666 | 10 ± 0.3 | 7 ± 2.3 | 17 ± 0.7
| 1,000 | 15 ± 2.4 | 10 ± 2.3 | 14 ± 2.7
| 1,666 | | 12 ± 1.0 | 16 ± 3.5
| 3,333 | 38 ± 5.6 | 19 ± 2.3 | 42 ± 1.9
| 6,666 | 78 ± 7.2 | 19 ± 8.4 | 0 ± 0.0
| | | Weakly
Trial summary | | Positive | Positive | Equivocal
Positive control | | 334 ± 23.2 | 243 ± 4.9 | 307 ± 43.6
| | Trial 1 | | Trial 2
TA98 ^c^ | 0 | 19 ± 2.3 | | 29 ± 1.8 | 31 ± 3.2 | 20 ± 0.9
| 3 | | | 27 ± 1.5
| 10 | | | 22 ± 1.8
| 33 | 27 ± 4.5 | | 22 ± 3.0 | 26 ± 2.9 | 20 ± 2.3
| 100 | 29 ± 4.9 | | 20 ± 3.0 | 31 ± 3.8 | 26 ± 2.3
| 333 | 30 ± 0.9 | | 24 ± 4.8 | 22 ± 2.4 | 20 ± 0.3
| 1,000 | 32 ± 2.3 | | | 25 ± 3.2 | 22 ± 2.9
| 3,333 | 32 ± 5.2 | | | 17 ± 8.7 | 19 ± 2.2
Trial summary | | Equivocal | | Negative | Negative | Negative
Positive control | | 527 ± 18.6 | | 476 ± 20.2 | 486 ± 11.4 | 121 ± 7.4
TA98 ^e^ | 0 | 17 ± 0.3 | | | 22 ± 2.1 | 26 ± 1.5
| 33 | 19 ± 1.2 | | | 20 ± 2.4 | 17 ± 1.7
| 100 | 18 ± 2.0 | | | 26 ± 0.9 | 20 ± 3.2
| 333 | 19 ± 2.6 | | | 25 ± 2.5 | 12 ± 0.3
| 1,000 | 18 ± 1.5 | | | 21 ± 2.5 | 18 ± 2.0
| 3,333 | 11 ± 5.2 | | | 23 ± 3.2 | 25 ± 2.3
Trial summary | | Negative | | | Negative | Negative
Positive control | | 319 ± 7.7 | | | 841 ± 75.9 | 511 ± 34.1

a The study was performed at SRI International. The detailed protocol is presented by Zeiger et al. (1992). 0 µg/plate was the solvent control.

b Revertants are presented as mean ± standard error from three plates.

c Dimethylsulfoxide was the solvent.

d The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535) and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

e Water was the solvent.

TABLE D2 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of Tg.AC Hemizygous Mice Following Dermal Administration of Dichloroacetic Acid for 26 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise Value^c^ | PCEs^b^ (%)
Male
Water:Acetone^d^ | 0 | 13 | 1.35 ± 0.18 | | 2.8 ± 0.1
Dichloroacetic Acid | 31.25 | 14 | 1.25 ± 0.24 | 0.6218 | 2.9 ± 0.2
Dichloroacetic Acid | 125 | 14 | 1.18 ± 0.16 | 0.7084 | 2.8 ± 0.2
Dichloroacetic Acid | 500 | 12 | 0.71 ± 0.16 | 0.9865 | 3.2 ± 0.2
| | | P=0.989^e^
Female
Water:Acetone | 0 | 11 | 1.14 ± 0.20 | | 2.6 ± 0.2
Dichloroacetic Acid | 31.25 | 12 | 1.58 ± 0.17 | 0.0977 | 3.1 ± 0.2
Dichloroacetic Acid | 125 | 14 | 1.25 ± 0.23 | 0.3578 | 3.2 ± 0.2
Dichloroacetic Acid | 500 | 15 | 1.07 ± 0.15 | 0.5938 | 3.6 ± 0.2
| | | P=0.857

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.008 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE D3 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of Tg.AC Hemizygous Mice Following Administration of Dichloroacetic Acid in Drinking Water for 26 Weeks^a^

Compound | Exposure Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 14 | 1.43 ± 0.21 | | 3.1 ± 0.1
Dichloroacetic Acid | 500 | 13 | 0.96 ± 0.20 | 0.9411 | 3.4 ± 0.4
Dichloroacetic Acid | 1,000 | 11 | 1.50 ± 0.32 | 0.4178 | 2.8 ± 0.2
Dichloroacetic Acid | 2,000 | 14 | 1.39 ± 0.21 | 0.5448 | 2.9 ± 0.2
| | | P=0.343^e^
Female
Water | 0 | 15 | 1.17 ± 0.15 | | 3.7 ± 0.5
Dichloroacetic Acid | 500 | 8 | 1.13 ± 0.28 | 0.5499 | 3.3 ± 0.4
Dichloroacetic Acid | 1,000 | 13 | 1.35 ± 0.20 | 0.2744 | 3.1 ± 0.1
Dichloroacetic Acid | 2,000 | 10 | 1.25 ± 0.17 | 0.3960 | 3.1 ± 0.2
| | | P=0.346

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the untreated control group; significant at P≤0.008 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE D4 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of p53 Haploinsufficient Mice Following Administration of Dichloroacetic Acid in Drinking Water for 26 Weeks^a^

Compound | Exposure Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 15 | 1.60 ± 0.20 | | 2.7 ± 0.1
Dichloroacetic Acid | 500 | 15 | 1.90 ± 0.20 | 0.1897 | 2.8 ± 0.2
Dichloroacetic Acid | 1,000 | 15 | 1.53 ± 0.19 | 0.5818 | 2.7 ± 0.1
Dichloroacetic Acid | 2,000 | 15 | 1.80 ± 0.24 | 0.2761 | 2.6 ± 0.1
| | | P=0.384^e^
Female
Water | 0 | 15 | 1.00 ± 0.22 | | 3.0 ± 0.2
Dichloroacetic Acid | 500 | 15 | 0.83 ± 0.12 | 0.7500 | 2.6 ± 0.1
Dichloroacetic Acid | 1,000 | 14 | 1.04 ± 0.22 | 0.4464 | 2.4 ± 0.1
Dichloroacetic Acid | 2,000 | 14 | 1.18 ± 0.21 | 0.2571 | 2.4 ± 0.1
| | | P=0.169

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the untreated control group; significant at P≤0.008 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE D5 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of B6C3F_1_ Mice Following Administration of Dichloroacetic Acid in Drinking Water for 3 Months^a^

Compound | Exposure Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 10 | 2.30 ± 0.40 | | 3.0 ± 0.1
Dichloroacetic Acid | 67 | 10 | 2.10 ± 0.43 | 0.6186 | 2.6 ± 0.1
Dichloroacetic Acid | 125 | 10 | 2.70 ± 0.42 | 0.2856 | 2.4 ± 0.1
Dichloroacetic Acid | 250 | 10 | 2.90 ± 0.43 | 0.2024 | 2.5 ± 0.1
Dichloroacetic Acid | 500 | 10 | 2.60 ± 0.31 | 0.3339 | 2.4 ± 0.1
Dichloroacetic Acid | 1,000 | 10 | 1.60 ± 0.40 | 0.8691 | 2.3 ± 0.1
| | | P=0.887^e^
Female
Water | 0 | 10 | 1.80 ± 0.42 | | 2.3 ± 0.1
Dichloroacetic Acid | 67 | 10 | 2.00 ± 0.33 | 0.3727 | 2.5 ± 0.1
Dichloroacetic Acid | 125 | 10 | 2.30 ± 0.45 | 0.2172 | 2.5 ± 0.1
Dichloroacetic Acid | 250 | 10 | 2.00 ± 0.21 | 0.3727 | 2.6 ± 0.1
Dichloroacetic Acid | 500 | 10 | 2.60 ± 0.50 | 0.1136 | 2.5 ± 0.1
Dichloroacetic Acid | 1,000 | 10 | 3.30 ± 0.52 | 0.0177 | 2.5 ± 0.1
| | | P=0.007

a Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the untreated control group; significant at P≤0.005 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)