# APPENDIX C SUMMARY OF LESIONS IN p53 HAPLOINSUFFICIENT MICE IN THE DRINKING WATER STUDIES OF DICHLOROACETIC ACID

TABLE C1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System

TABLE C2 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%)
Inflammation, chronic active | 15 (100%) | 13 (87%) | 15 (100%) | 13 (87%)
Hepatocyte, fatty change | 10 (67%) | 2 (13%) | 1 (7%)
Hepatocyte, necrosis | 1 (7%) | | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 15 (100%) | 15 (100%) | 15 (100%) | 15 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 1 (7%) | | 1 (7%)
Hypertrophy | 1 (7%) | | 1 (7%) | 2 (13%)
Subcapsular, hyperplasia | 4 (27%) | | 3 (20%) | 3 (20%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | 3 (20%) | 2 (13%) | 2 (13%) | 1 (7%)
Pars distalis, hyperplasia | | | 6 (40%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | | | | 2 (13%)
Follicle, cyst | | | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Granuloma sperm | 1 (7%)
Infiltration cellular, lymphocyte | | | 3 (20%)
Inflammation, chronic active | | | 1 (7%)
Testes | (15) | (15) | (15) | (15)
Mineralization | 1 (7%) | | 1 (7%)
Germinal epithelium, degeneration | 2 (13%) | 4 (27%) | 3 (20%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | | | 2 (13%) | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | 1 (7%) | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Cyst | 9 (60%) | 9 (60%) | 9 (60%) | 9 (60%)
Ectopic parathyroid gland | | | 1 (7%)
Hyperplasia, lymphoid | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Mineralization | | | 1 (7%)
Nephropathy | 8 (53%) | 10 (67%) | 11 (73%) | 12 (80%)
Renal tubule, dilatation | 2 (13%) | 4 (27%) | | 2 (13%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C3 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | | | 1
Natural death | | | 1
Survivors
Terminal sacrifice | 15 | 15 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Intestine large, cecum | (15) | (15) | (15) | (15)
Liver | (15) | (15) | (15) | (15)
Mesentery | | | | (1)
Endocrine System
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, adenoma | | 1 (7%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Uterus | (15) | (15) | (15) | (15)
Polyp stromal | 1 (7%)
Hematopoietic System
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (15) | (15)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Lymphoma malignant | | | 1 (7%) | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 1 | 1 | 1
Total primary neoplasms | 1 | 1 | 1 | 1
Total animals with benign neoplasms | 1 | 1
Total benign neoplasms | 1 | 1
Total animals with malignant neoplasms | | | 1 | 1
Total malignant neoplasms | | | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | | | 1
Natural death | | | 1
Survivors
Terminal sacrifice | 15 | 15 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Inflammation, chronic active | 15 (100%) | 14 (93%) | 13 (87%) | 14 (93%)
Hepatocyte, necrosis | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 3 (20%) | 15 (100%) | 15 (100%) | 15 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 4 (27%) | 2 (13%) | 1 (7%)
Subcapsular, hyperplasia | 14 (93%) | 14 (93%) | 15 (100%) | 14 (93%)
Parathyroid gland | (1)
Cyst | 1 (100%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | 1 (7%) | 2 (13%) | 3 (20%)
Pars distalis, hyperplasia | 1 (7%) | | 3 (20%) | 5 (33%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | 1 (7%)
Infiltration cellular, lymphocyte | 2 (13%) | 1 (7%)
Follicle, degeneration | 1 (7%) | 3 (20%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Cyst | | 2 (13%) | 1 (7%) | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Inflammation, chronic active | 1 (7%) | | | 1 (7%)
Endometrium, hyperplasia, cystic | 8 (53%) | 12 (80%) | 13 (87%) | 13 (87%)
Hematopoietic System
Lymph node | | (1)
Mediastinal, hyperplasia, lymphoid | | 1 (100%)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | 1 (7%) | | 4 (27%) | 4 (27%)
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Cyst | 10 (67%) | 11 (73%) | 11 (73%) | 12 (80%)
Ectopic parathyroid gland | 2 (13%) | 2 (13%) | 1 (7%) | 2 (13%)
Thymocyte, necrosis | | 6 (40%) | 2 (13%) | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 2 (13%) | 3 (20%) | 1 (7%)
Alveolus, infiltration cellular, histiocyte | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Cyst | | | | 1 (7%)
Mineralization | | | 4 (27%) | 1 (7%)
Nephropathy | 3 (20%) | 11 (73%) | 7 (47%) | 9 (60%)
Renal tubule, dilatation | | | 2 (13%) | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C5 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Natural deaths | 1 | | 1
Survivors
Terminal sacrifice | 9 | 10 | 9 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hepatocellular adenoma | | 2 (20%)
Osteosarcoma, metastatic, bone | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Thymoma malignant, metastatic, thymus | | 1 (10%)
Hematopoietic System
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Thymoma malignant | | 1 (10%)
Musculoskeletal System
Bone | (1) | (1)
Osteosarcoma | 1 (100%) | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Thymoma malignant, metastatic, thymus | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Thymoma malignant, metastatic, thymus | | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Lymphoma malignant | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Integumentary System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 3 | 1
Total primary neoplasms | 1 | 4 | 1
Total animals with benign neoplasms | | 2
Total benign neoplasms | | 2
Total animals with malignant neoplasms | 1 | 2 | 1
Total malignant neoplasms | 1 | 2 | 1
Total animals with metastatic neoplasms | 1 | 1
Total metastatic neoplasms | 1 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C6 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Natural deaths | 1 | | 1
Survivors
Terminal sacrifice | 9 | 10 | 9 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%)
Inflammation, chronic active | 9 (90%) | 8 (80%) | 7 (70%) | 9 (90%)
Hepatocyte, fatty change | 6 (60%) | 5 (50%)
Hepatocyte, necrosis | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%) | | 1 (10%)
Ulcer | 1 (10%) | | 1 (10%)
Epithelium, hyperkeratosis | 1 (10%) | | 1 (10%)
Epithelium, hyperplasia | 1 (10%) | | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hypertrophy | 3 (30%) | 3 (30%) | 1 (10%)
Subcapsular, hyperplasia | 3 (30%) | 5 (50%) | 3 (30%) | 3 (30%)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | 4 (40%) | 2 (20%) | 2 (20%)
Thyroid gland | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | 1 (10%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Degeneration | | | | 1 (10%)
Inflammation, chronic active | 3 (30%) | 2 (20%) | 1 (10%) | 3 (30%)
Testes | (10) | (10) | (10) | (10)
Mineralization | | | | 1 (10%)
Germinal epithelium, degeneration | 5 (50%) | 4 (40%) | 2 (20%) | 4 (40%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | 1 (10%)
Cyst | 6 (60%) | 3 (30%) | 2 (20%) | 2 (20%)
Ectopic parathyroid gland | | | 2 (20%) | 3 (30%)
Hyperplasia, lymphoid | 1 (10%) | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Thrombosis | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Hydronephrosis | | | | 1 (10%)
Metaplasia, osseous | | | | 1 (10%)
Mineralization | 1 (10%)
Nephropathy | 9 (90%) | 6 (60%) | 8 (80%) | 8 (80%)
Renal tubule, dilatation | 1 (10%) | 2 (20%) | | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C7 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | | 1
Natural death | | | | 1
Survivors
Terminal sacrifice | 10 | 9 | 10 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Genital System
Uterus | (10) | (10) | (10) | (10)
Polyp stromal | | 1 (10%)
Integumentary System
Skin | | (1) | | (1)
Subcutaneous tissue, rhabdomyosarcoma | | | | 1 (100%)
Musculoskeletal System
Bone | | (1) | | (1)
Osteosarcoma | | 1 (100%) | | 1 (100%)
Skeletal muscle | | (1) | | (1)
Osteosarcoma, metastatic, bone | | 1 (100%) | | 1 (100%)
Nervous System
Spinal cord | | (1)
Osteosarcoma, metastatic, bone | | 1 (100%)
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | | 2 | | 2
Total primary neoplasms | | 2 | | 2
Total animals with benign neoplasms | | 1
Total benign neoplasms | | 1
Total animals with malignant neoplasms | | 1 | | 2
Total malignant neoplasms | | 1 | | 2
Total animals with metastatic neoplasms | | 1 | | 1
Total metastatic neoplasms | | 2 | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C8 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | | 1
Natural death | | | | 1
Survivors
Terminal sacrifice | 10 | 9 | 10 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Inflammation, chronic active | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%)
Hepatocyte, fatty change | 1 (10%)
Hepatocyte, necrosis | | | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | | 2 (20%)
Subcapsular, hyperplasia | 10 (100%) | 10 (100%) | 9 (90%) | 10 (100%)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | | | 1 (10%) | 1 (10%)
Pars distalis, hyperplasia | | 1 (10%) | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Ectopic thymus | | | | 1 (10%)
Infiltration cellular, lymphocyte | | | | 2 (20%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Cyst | | 1 (10%) | 1 (10%) | 7 (70%)
Uterus | (10) | (10) | (10) | (10)
Inflammation, chronic active | 2 (20%) | 1 (10%) | 1 (10%)
Endometrium, hyperplasia, cystic | 7 (70%) | 9 (90%) | 9 (90%) | 9 (90%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | | 2 (20%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | 2 (20%) | | 2 (20%)
Hyperplasia, lymphoid | | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Cyst | 9 (90%) | 8 (80%) | 7 (70%) | 8 (80%)
Ectopic parathyroid gland | | 1 (10%)
Integumentary System
Skin | | (1) | | (1)
Hyperkeratosis | | 1 (100%)
Hyperplasia | | 1 (100%)
Inflammation, chronic active | | 1 (100%)
Ulcer | | 1 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Metaplasia, osseous | | | 1 (10%)
Mineralization | | 2 (20%) | 3 (30%)
Nephropathy | 4 (40%) | 4 (40%) | 7 (70%) | 5 (50%)
Renal tubule, dilatation | | | 1 (10%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion