# APPENDIX B SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE DRINKING WATER STUDIES OF DICHLOROACETIC ACID

TABLE B1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | 2 | 4 | 1
Survivors
Terminal sacrifice | 14 | 13 | 11 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | | | (1) | (1)
Carcinoma | | | 1 (100%) | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 1 (7%) | 3 (20%) | 5 (33%) | 3 (20%)
Squamous cell papilloma, multiple | 3 (20%) | 2 (13%) | 2 (13%) | 3 (20%)
Tooth | (1) | (3) | (4)
Odontogenic tumor | 1 (100%) | 3 (100%) | 3 (75%)
Odontogenic tumor, multiple | | | 1 (25%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (14) | (15) | (15) | (15)
Hematopoietic System
Spleen | (15) | (15) | (15) | (15)
Integumentary System
Skin | (4) | (4) | (4) | (6)
Squamous cell papilloma | 2 (50%) | 3 (75%) | 2 (50%) | 3 (50%)
Squamous cell papilloma, multiple | | 1 (25%) | 2 (50%) | 1 (17%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar carcinoma | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 11 | 12 | 8
Total primary neoplasms | 7 | 13 | 17 | 11
Total animals with benign neoplasms | 6 | 8 | 8 | 7
Total benign neoplasms | 6 | 9 | 11 | 10
Total animals with malignant neoplasms | | 1 | 2 | 1
Total malignant neoplasms | | 1 | 2 | 1
Total animals with uncertain neoplasms-benign or malignant | 1 | 3 | 4
Total uncertain neoplasms | 1 | 3 | 4

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | 2 | 4 | 1
Survivors
Terminal sacrifice | 14 | 13 | 11 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | 3 (20%) | 2 (13%) | 1 (7%)
Inflammation, chronic active | 9 (60%) | 13 (87%) | 12 (80%) | 11 (73%)
Hepatocyte, fatty change | | 3 (20%) | 1 (7%)
Hepatocyte, necrosis | | 1 (7%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 7 (47%) | 13 (87%) | 15 (100%) | 15 (100%)
Mesentery | (1) | (1) | (2)
Fat, fibrosis | | 1 (100%) | 1 (50%)
Fat, hemorrhage | 1 (100%) | 1 (100%) | 2 (100%)
Fat, inflammation, chronic active | 1 (100%) | 1 (100%) | 2 (100%)
Fat, necrosis | 1 (100%) | 1 (100%) | 2 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | 1 (7%)
Epithelium, hyperkeratosis | | | 1 (7%) | 1 (7%)
Epithelium, hyperplasia | 2 (13%) | 4 (27%) | 3 (20%) | 6 (40%)
Stomach, glandular | | | | (1)
Glands, ectasia | | | | 1 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 1 (7%) | | 1 (7%) | 2 (13%)
Hypertrophy | 8 (53%) | 9 (60%) | 8 (53%) | 8 (53%)
Subcapsular, hyperplasia | 2 (13%) | | 2 (13%)
Pituitary gland | (14) | (15) | (15) | (15)
Pars distalis, cyst | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Infiltration cellular, lymphocyte | | 1 (7%)
Follicle, degeneration | 7 (47%) | 8 (53%) | 5 (33%) | 5 (33%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Degeneration | 2 (13%) | 2 (13%) | 2 (13%) | 2 (13%)
Preputial gland | | (2) | (1)
Duct, ectasia | | 2 (100%) | 1 (100%)
Seminal vesicle | (1)
Inflammation, chronic active | 1 (100%)
Testes | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)
Germinal epithelium, degeneration | 2 (13%) | 2 (13%) | 1 (7%) | 2 (13%)
Hematopoietic System
Lymph node, mandibular | (15) | (14) | (15) | (14)
Hyperplasia, lymphoid | 1 (7%) | 3 (21%) | 2 (13%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 2 (13%) | 1 (7%)
Thymus | (15) | (15) | (14) | (14)
Atrophy | 1 (7%) | 3 (20%) | 4 (29%)
Cyst | 1 (7%) | 2 (13%) | 1 (7%) | 2 (14%)
Integumentary System
Skin | (4) | (4) | (4) | (6)
Inflammation, chronic active | | | | 1 (17%)
Epidermis, hyperplasia | 1 (25%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 4 (27%) | 2 (13%) | 1 (7%)
Alveolar epithelium, hyperplasia | | | 1 (7%) | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 1 (7%)
Necrosis | | 1 (7%)
Nephropathy | 10 (67%) | 9 (60%) | 12 (80%) | 14 (93%)
Renal tubule, dilatation | 1 (7%) | | | 2 (13%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | 4 | 1 | 4
Natural deaths | | 3 | 1 | 1
Survivors
Terminal sacrifice | 15 | 8 | 13 | 10
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Intestine large, rectum | (2) | | (2)
Anus, squamous cell papilloma | 2 (100%) | | 2 (100%)
Liver | (15) | (15) | (15) | (15)
Salivary glands | (1)
Carcinoma | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 4 (27%) | 3 (20%) | 2 (13%) | 4 (27%)
Squamous cell papilloma, multiple | 1 (7%) | 2 (13%) | 3 (20%)
Tooth | (2) | (4) | (2) | (2)
Odontogenic tumor | 2 (100%) | 4 (100%) | 2 (100%) | 2 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (15) | (14) | (15) | (15)
Genital System
Ovary | (15) | (15) | (15) | (15)
Hematopoietic System
Lymph node | (1)
Lymph node, mandibular | (15) | (14) | (15) | (15)
Lymph node, mesenteric | (15) | (13) | (15) | (15)
Spleen | (15) | (15) | (15) | (15)
Integumentary System
Skin | (4) | (4) | (2) | (8)
Squamous cell papilloma | 4 (100%) | 4 (100%) | 1 (50%) | 4 (50%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar carcinoma | | 1 (7%) | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | 1 (7%)
Lymphoma malignant | | | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 10 | 9 | 10
Total primary neoplasms | 15 | 15 | 10 | 12
Total animals with benign neoplasms | 8 | 8 | 8 | 7
Total benign neoplasms | 11 | 10 | 8 | 9
Total animals with malignant neoplasms | 2 | 1 | | 1
Total malignant neoplasms | 2 | 1 | | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 4 | 2 | 2
Total uncertain neoplasms | 2 | 4 | 2 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | 4 | 1 | 4
Natural deaths | | 3 | 1 | 1
Survivors
Terminal sacrifice | 15 | 8 | 13 | 10
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 2 (13%)
Inflammation, chronic active | 14 (93%) | 10 (67%) | 12 (80%) | 12 (80%)
Hepatocyte, fatty change | 2 (13%) | 3 (20%)
Hepatocyte, necrosis | 1 (7%) | 5 (33%) | 1 (7%) | 3 (20%)
Hepatocyte, vacuolization cytoplasmic | 6 (40%) | 10 (67%) | 14 (93%) | 14 (93%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperkeratosis | | 5 (33%) | 1 (7%) | 1 (7%)
Epithelium, hyperplasia | 2 (13%) | 5 (33%) | 2 (13%) | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 2 (13%) | 5 (33%) | 4 (27%) | 7 (47%)
Subcapsular, hyperplasia | 10 (67%) | 7 (47%) | 3 (20%) | 9 (60%)
Pituitary gland | (15) | (14) | (15) | (15)
Pars distalis, cyst | 1 (7%) | | 3 (20%) | 4 (27%)
Thyroid gland | (15) | (15) | (15) | (15)
Follicle, degeneration | 4 (27%) | 4 (27%) | 4 (27%) | 3 (20%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | 1 (7%) | 1 (7%) | 2 (13%)
Inflammation, chronic active | | 1 (7%)
Pigmentation, hemosiderin | | | | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 9 (60%) | 8 (53%) | 10 (67%) | 5 (33%)
Hematopoietic System
Lymph node, mandibular | (15) | (14) | (15) | (15)
Hyperplasia, lymphoid | 3 (20%) | 2 (14%) | 3 (20%) | 2 (13%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | | 1 (7%) | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%)
Necrosis | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | 1 (7%) | 4 (27%) | 3 (20%) | 3 (20%)
Cyst | 4 (27%) | 3 (20%) | 4 (27%) | 1 (7%)
Integumentary System
Skin | (4) | (4) | (2) | (8)
Hyperkeratosis | | | 1 (50%)
Epidermis, hyperplasia | | | 1 (50%) | 4 (50%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Inflammation, chronic active | 1 (7%) | | | 1 (7%)
Necrosis | | | 1 (7%)
Nephropathy | 5 (33%) | 6 (40%) | 5 (33%) | 7 (47%)
Cortex, cyst | 1 (7%)
Papilla, necrosis | | | | 1 (7%)
Renal tubule, dilatation | 3 (20%) | 1 (7%) | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund sacrifice | | 1
Natural death | 1
Survivors
Terminal sacrifice | 9 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hepatocellular adenoma | | | | 1 (10%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 3 (30%) | 1 (10%) | 2 (20%)
Squamous cell papilloma, multiple | 3 (30%) | 6 (60%) | 5 (50%) | 5 (50%)
Tooth | (2) | (1) | (1) | (2)
Odontogenic tumor | | 1 (100%) | 1 (100%) | 1 (50%)
Odontogenic tumor, multiple | 2 (100%) | | | 1 (50%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Integumentary System
Skin | (9) | (9) | (9) | (8)
Squamous cell papilloma | | 1 (11%)
Squamous cell papilloma, multiple | 9 (100%) | 8 (89%) | 9 (100%) | 8 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | 1 (10%) | | 7 (70%) | 3 (30%)
Alveolar/bronchiolar adenoma, multiple | | 2 (20%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 9 | 10 | 9
Total primary neoplasms | 17 | 21 | 24 | 21
Total animals with benign neoplasms | 9 | 9 | 10 | 9
Total benign neoplasms | 15 | 20 | 22 | 19
Animals with malignant neoplasms | | | 1
Total malignant neoplasms | | | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 1 | 1 | 2
Total uncertain neoplasms | 2 | 1 | 1 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | | 1
Natural death | 1
Survivors
Terminal sacrifice | 9 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%)
Inflammation, acute | | 1 (10%) | 1 (10%) | 1 (10%)
Inflammation, chronic active | 9 (90%) | 7 (70%) | 5 (50%) | 7 (70%)
Hepatocyte, necrosis | 1 (10%) | 1 (10%) | 1 (10%) | 3 (30%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 10 (100%) | 9 (90%) | 10 (100%)
Mesentery | (1) | | (3) | (1)
Fat, fibrosis | | | 2 (67%) | 1 (100%)
Fat, inflammation, chronic active | | | 1 (33%) | 1 (100%)
Fat, necrosis | 1 (100%) | | 3 (100%) | 1 (100%)
Fat, pigmentation | | | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperplasia | 3 (30%) | | | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | 1 (10%) | 1 (10%) | | 1 (10%)
Atypia cellular | | | 1 (10%)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%)
Hypertrophy | 8 (80%) | 6 (60%) | 9 (90%) | 7 (70%)
Subcapsular, hyperplasia | 2 (20%) | 1 (10%) | 1 (10%)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | | 2 (20%) | 1 (10%) | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Ectopic thymus | | | 1 (10%)
Infiltration cellular, lymphocyte | 1 (10%) | 1 (10%)
Follicle, degeneration | 3 (30%) | 9 (90%) | 5 (50%) | 4 (40%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Cyst | | | | 1 (10%)
Degeneration | | 1 (10%) | 1 (10%) | 3 (30%)
Inflammation, chronic active | 1 (10%)
Preputial gland | (2) | (4) | (2)
Inflammation, chronic active | 1 (50%)
Duct, ectasia | 2 (100%) | 4 (100%) | 2 (100%)
Seminal vesicle | (1) | (1)
Inflammation, chronic active | 1 (100%)
Inflammation, suppurative | | 1 (100%)
Testes | (10) | (10) | (10) | (10)
Cyst | | | 1 (10%)
Mineralization | | | | 1 (10%)
Germinal epithelium, degeneration | | 1 (10%) | 1 (10%) | 3 (30%)
Interstitial cell, hyperplasia | | | 1 (10%) | 1 (10%)
Hematopoietic System
Lymph node | | (1) | (2)
Lumbar, hematopoietic cell proliferation | | 1 (100%)
Lumbar, hyperplasia, lymphoid | | 1 (100%)
Mediastinal, hematopoietic cell proliferation | | 1 (100%)
Mediastinal, hyperplasia, lymphoid | | 1 (100%)
Mediastinal, infiltration cellular, mast cell | | | 1 (50%)
Mediastinal, infiltration cellular, histiocyte | | | 1 (50%)
Renal, hematopoietic cell proliferation | | 1 (100%)
Renal, hyperplasia, lymphoid | | 1 (100%)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | | 1 (10%) | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%)
Necrosis | 1 (10%)
Thymus | (10) | (10) | (9) | (10)
Atrophy | 2 (20%) | 1 (10%) | 1 (11%)
Cyst | 2 (20%) | 3 (30%) | 4 (44%) | 3 (30%)
Ectopic parathyroid gland | | | 2 (22%)
Integumentary System
Skin | (9) | (9) | (9) | (8)
Inflammation, chronic active | | | 1 (11%) | 1 (13%)
Epidermis, hyperplasia | 5 (56%) | 4 (44%) | | 1 (13%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Hemorrhage | 1 (10%)
Infiltration cellular, polymorphonuclear | 1 (10%)
Inflammation, chronic active | 2 (20%) | 1 (10%)
Alveolar epithelium, hyperplasia | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Infarct | | 1 (10%)
Inflammation, chronic active | 1 (10%)
Mineralization | 1 (10%)
Necrosis | 1 (10%)
Nephropathy | 9 (90%) | 8 (80%) | 7 (70%) | 10 (100%)
Pelvis, inflammation, chronic | | 1 (10%)
Renal tubule, cyst | | | 1 (10%)
Renal tubule, dilatation | 4 (40%) | 6 (60%) | 6 (60%) | 5 (50%)
Renal tubule, nephropathy | | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | 1 | 2
Natural deaths | 2 | 1 | 2
Survivors
Terminal sacrifice | 7 | 9 | 7 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Intestine large, rectum | (1)
Anus, squamous cell papilloma | 1 (100%)
Liver | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 5 (50%) | 1 (10%) | 3 (30%) | 2 (20%)
Squamous cell papilloma, multiple | 1 (10%) | 6 (60%) | 4 (40%) | 4 (40%)
Tooth | (1) | (2) | (3) | (3)
Odontogenic tumor | 1 (100%) | 2 (100%) | 3 (100%) | 3 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Genital System
Ovary | (10) | (10) | (10) | (10)
Oviduct | | (1)
Adenoma | | 1 (100%)
Hematopoietic System
Lymph node | | (1) | | (1)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (9) | (10)
Integumentary System
Skin | (6) | (7) | (7) | (7)
Squamous cell papilloma | 1 (17%) | 2 (29%) | 4 (57%) | 4 (57%)
Squamous cell papilloma, multiple | 5 (83%) | 5 (71%) | 2 (29%) | 3 (43%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | | 2 (20%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 3 (30%) | | 1 (10%) | 1 (10%)
Lymphoma malignant | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 9 | 8 | 9
Total primary neoplasms | 17 | 18 | 17 | 19
Total animals with benign neoplasms | 7 | 8 | 7 | 8
Total benign neoplasms | 13 | 15 | 13 | 15
Total animals with malignant neoplasms | 3 | 1 | 1 | 1
Total malignant neoplasms | 3 | 1 | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 1 | 2 | 3 | 3
Total uncertain neoplasms | 1 | 2 | 3 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 41-Week Drinking Water Study of Dichloroacetic Acid^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | 1 | 2
Natural deaths | 2 | 1 | 2
Survivors
Terminal sacrifice | 7 | 9 | 7 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Inflammation, chronic active | 7 (70%) | 10 (100%) | 9 (90%) | 8 (80%)
Hepatocyte, fatty change | | | | 1 (10%)
Hepatocyte, necrosis | 1 (10%) | 1 (10%) | 1 (10%) | 4 (40%)
Hepatocyte, vacuolization cytoplasmic | 7 (70%) | 9 (90%) | 9 (90%) | 10 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperkeratosis | | 1 (10%)
Epithelium, hyperplasia | | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | 2 (20%) | 2 (20%) | 2 (20%) | 3 (30%)
Subcapsular, hyperplasia | 3 (30%) | 5 (50%) | 4 (40%) | 8 (80%)
Adrenal medulla | (10) | (10) | (10) | (10)
Mineralization | | | 1 (10%)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | 2 (20%) | 2 (20%) | 2 (20%) | 2 (20%)
Thyroid gland | (10) | (10) | (10) | (10)
Ectopic thymus | | | | 1 (10%)
Follicle, degeneration | 3 (30%) | 6 (60%) | 5 (50%) | 5 (50%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Cyst | | 7 (70%) | 4 (40%) | 1 (10%)
Inflammation, chronic active | | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Endometrium, hyperplasia, cystic | 7 (70%) | 9 (90%) | 7 (70%) | 7 (70%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | | 1 (10%) | 1 (10%) | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | 1 (10%)
Hematopoietic cell proliferation | | 1 (10%) | | 1 (10%)
Thymus | (10) | (10) | (9) | (10)
Atrophy | 3 (30%) | 1 (10%) | 1 (11%) | 1 (10%)
Cyst | 3 (30%) | 4 (40%) | 2 (22%) | 5 (50%)
Ectopic parathyroid gland | 1 (10%)
Thrombosis | 1 (10%)
Thymocyte, necrosis | | | | 1 (10%)
Integumentary System
Skin | (6) | (7) | (7) | (7)
Hyperkeratosis | | | 1 (14%)
Inflammation, chronic active | | | 1 (14%)
Epidermis, hyperplasia | 1 (17%) | | 2 (29%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Infarct | | | 1 (10%)
Mineralization | | | 1 (10%)
Nephropathy | 3 (30%) | 5 (50%) | 2 (20%) | 7 (70%)
Glomerulus, inflammation, membranoproliferative | 3 (30%) | | 1 (10%) | 1 (10%)
Renal tubule, dilatation | 3 (30%) | 1 (10%) | 2 (20%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Respiratory
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion