# APPENDIX A SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE DERMAL STUDIES OF DICHLOROACETIC ACID

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | | | 2
Natural deaths | | 1 | 1 | 1
Survivors
Terminal sacrifice | 13 | 14 | 14 | 12
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Salivary glands | (1)
Carcinoma | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | | 4 (27%) | 3 (20%) | 3 (20%)
Squamous cell papilloma, multiple | 1 (7%) | 2 (13%)
Tooth | (2) | (3) | (1) | (4)
Odontogenic tumor | 2 (100%) | 3 (100%) | 1 (100%) | 4 (100%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Squamous cell papilloma | 5 (33%) | 3 (20%) | 2 (13%) | 3 (20%)
Squamous cell papilloma, multiple | | 2 (13%) | 1 (7%) | 2 (13%)
Site of application, keratoacanthoma | | | | 1 (7%)
Site of application, squamous cell papilloma | | | 1 (7%) | 1 (7%)
Site of application, squamous cell papilloma, multiple | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 1 (7%) | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | 7 | 11 | 8 | 8
Total primary neoplasms | 10 | 14 | 9 | 15
Total animals with benign neoplasms | 6 | 10 | 8 | 7
Total benign neoplasms | 7 | 11 | 8 | 11
Total animals with malignant neoplasms | 1
Total malignant neoplasms | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 3 | 1 | 4
Total uncertain neoplasms | 2 | 3 | 1 | 4

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | | | 2
Natural deaths | | 1 | 1 | 1
Survivors
Terminal sacrifice | 13 | 14 | 14 | 12
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 3 (20%)
Inflammation, chronic active | 2 (13%) | 8 (53%) | 4 (27%) | 2 (13%)
Pigmentation | | | | 1 (7%)
Hepatocyte, necrosis | 1 (7%) | 2 (13%) | | 2 (13%)
Hepatocyte, vacuolization cytoplasmic | 3 (20%) | 4 (27%) | 14 (93%) | 15 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperkeratosis | | | | 1 (7%)
Epithelium, hyperplasia | 1 (7%) | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hypertrophy | 11 (73%) | 7 (47%) | 7 (47%) | 7 (47%)
Subcapsular, hyperplasia | 4 (27%) | 1 (7%) | 2 (13%)
Parathyroid gland | | (1)
Cyst | | 1 (100%)
Pituitary gland | (15) | (15) | (14) | (15)
Pars distalis, cyst | | 1 (7%) | | 3 (20%)
Thyroid gland | (15) | (15) | (15) | (15)
Follicle, degeneration | 3 (20%) | 3 (20%) | 2 (13%) | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Degeneration | 2 (13%) | 1 (7%) | 1 (7%) | 1 (7%)
Inflammation, chronic active | | | | 1 (7%)
Testes | (15) | (15) | (15) | (15)
Cyst | | 1 (7%) | 1 (7%) | 1 (7%)
Germinal epithelium, degeneration | 2 (13%) | 1 (7%) | 1 (7%) | 2 (13%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (14)
Hyperplasia, lymphoid | | 2 (13%) | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 3 (20%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | 1 (7%) | 1 (7%) | | 2 (13%)
Cyst | 6 (40%) | 1 (7%) | 4 (27%) | 2 (13%)
Thymocyte, necrosis | | | | 2 (13%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Epidermis, hyperplasia | 2 (13%) | 3 (20%) | 2 (13%) | 3 (20%)
Site of application, epidermis, hyperkeratosis | 2 (13%) | 7 (47%) | 15 (100%) | 14 (93%)
Site of application, epidermis, hyperplasia | | 2 (13%) | 11 (73%) | 13 (87%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 1 (7%) | | 1 (7%)
Pigmentation | | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Nephropathy | 7 (47%) | 7 (47%) | 11 (73%) | 13 (87%)
Renal tubule, dilatation | 4 (27%) | 2 (13%) | 2 (13%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | 1
Natural deaths | 4 | 2 | 1
Survivors
Terminal sacrifice | 11 | 12 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | (1)
Carcinoma | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 4 (27%) | 5 (33%) | 4 (27%) | 5 (33%)
Squamous cell papilloma, multiple | 3 (20%) | 1 (7%) | 4 (27%) | 2 (13%)
Tooth | (5) | (2) | (5) | (2)
Odontogenic tumor | 5 (100%) | 2 (100%) | 5 (100%) | 2 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (15) | (15) | (15) | (15)
Hematopoietic System
Spleen | (15) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Squamous cell papilloma | 6 (40%) | 5 (33%) | 6 (40%) | 2 (13%)
Squamous cell papilloma, multiple | | 3 (20%) | 2 (13%)
Site of application, squamous cell papilloma | | | | 2 (13%)
Respiratory System
Lung | (15) | (15) | (15) | (14)
Alveolar/bronchiolar adenoma | | 1 (7%) | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 12 | 12 | 10
Total primary neoplasms | 20 | 17 | 22 | 14
Total animals with benign neoplasms | 8 | 11 | 11 | 10
Total benign neoplasms | 13 | 15 | 17 | 11
Total animals with malignant neoplasms | 2 | | | 1
Total malignant neoplasms | 2 | | | 1
Total animals with uncertain neoplasms-benign or malignant | 5 | 2 | 5 | 2
Total uncertain neoplasms | 5 | 2 | 5 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary tumors: all tumors except metastatic tumors

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | 1
Natural deaths | 4 | 2 | 1
Survivors
Terminal sacrifice | 11 | 12 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Inflammation, chronic active | 11 (73%) | 13 (87%) | 14 (93%) | 11 (73%)
Hepatocyte, necrosis | 1 (7%) | | | 3 (20%)
Hepatocyte, vacuolization cytoplasmic | 6 (40%) | 4 (27%) | 14 (93%) | 15 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperkeratosis | 1 (7%)
Epithelium, hyperplasia | 1 (7%) | 1 (7%) | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | | 2 (13%) | 7 (47%) | 4 (27%)
Subcapsular, hyperplasia | 5 (33%) | 8 (53%) | 6 (40%) | 9 (60%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | 3 (20%) | 4 (27%) | 3 (20%) | 3 (20%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | | 1 (7%)
Follicle, degeneration | 5 (33%) | 4 (27%) | 2 (13%) | 1 (7%)
Follicular cell, hyperplasia | | | 1 (7%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Cyst | 3 (20%) | 2 (13%) | 1 (7%) | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 10 (67%) | 12 (80%) | 10 (67%) | 14 (93%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | 3 (20%) | 1 (7%) | 4 (27%) | 2 (13%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | 3 (20%) | 1 (7%) | 1 (7%)
Cyst | 3 (20%) | 8 (53%) | 7 (47%) | 9 (60%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Hyperkeratosis | 1 (7%) | | 1 (7%)
Inflammation, chronic active | 1 (7%)
Epidermis, hyperplasia | 3 (20%) | 1 (7%) | 1 (7%) | 2 (13%)
Site of application, epidermis, hyperkeratosis | 8 (53%) | 9 (60%) | 14 (93%) | 14 (93%)
Site of application, epidermis, hyperplasia | | 1 (7%) | 10 (67%) | 13 (87%)
Respiratory System
Lung | (15) | (15) | (15) | (14)
Inflammation, chronic active | 1 (7%) | | | 1 (7%)
Thrombosis | | | | 1 (7%)
Alveolar epithelium, hyperplasia | | | 1 (7%) | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Nephropathy | 3 (20%) | 6 (40%) | 5 (33%) | 5 (33%)
Renal tubule, dilatation | 2 (13%) | 3 (20%) | 3 (20%) | 1 (7%)
Renal tubule, hyperplasia | | | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 3 | 1 | 2
Natural deaths | | 1 | 1 | 1
Survivors
Terminal sacrifice | 9 | 6 | 8 | 7
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Pancreas | (1)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 2 (20%) | | 4 (40%)
Squamous cell papilloma, multiple | 5 (50%) | 4 (40%) | 8 (80%) | 3 (30%)
Tooth | (1) | (4) | (2) | (2)
Odontogenic tumor | 1 (100%) | 4 (100%) | 2 (100%) | 1 (50%)
Odontogenic tumor, multiple | | | | 1 (50%)
Hematopoietic System
Lymph node | (1) | (1)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Thymus | (9) | (10) | (10) | (9)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | | | 7 (70%)
Squamous cell papilloma, multiple | 6 (60%) | 4 (40%) | 7 (70%) | 2 (20%)
Site of application, squamous cell papilloma | | | 1 (10%) | 2 (20%)
Site of application, squamous cell papilloma, multiple | | | 1 (10%) | 6 (60%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | 1 (10%) | 2 (20%)
Nose | | | | (1)
Glands, carcinoma | | | | 1 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 1 (10%)
Lymphoma malignant | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 10 | 9 | 10
Total primary neoplasms | 17 | 15 | 20 | 29
Total animals with benign neoplasms | 10 | 7 | 9 | 10
Total benign neoplasms | 15 | 10 | 18 | 26
Total animals with malignant neoplasms | 1 | 1 | | 1
Total malignant neoplasms | 1 | 1 | | 1
Total animals with uncertain neoplasms-benign or malignant | 1 | 4 | 2 | 2
Total uncertain neoplasms | 1 | 4 | 2 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 3 | 1 | 2
Natural deaths | | 1 | 1 | 1
Survivors
Terminal sacrifice | 9 | 6 | 8 | 7
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Cyst | | | 1 (10%)
Inflammation, chronic active | 6 (60%) | 7 (70%) | 5 (50%) | 5 (50%)
Mineralization | 1 (10%)
Hepatocyte, necrosis | 1 (10%) | | 2 (20%) | 6 (60%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 7 (70%) | 8 (80%) | 10 (100%)
Mesentery | (1) | | (2)
Fat, fibrosis | | | 2 (100%)
Fat, mineralization | 1 (100%) | | 1 (50%)
Fat, necrosis | 1 (100%) | | 2 (100%)
Salivary glands | | | (1) | (1)
Atrophy | | | 1 (100%) | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperkeratosis | | 1 (10%)
Epithelium, hyperplasia | | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | | | | 1 (10%)
Hypertrophy | 8 (80%) | 8 (80%) | 6 (60) | 7 (70%)
Subcapsular, hyperplasia | | 1 (10%) | 1 (10%) | 1 (10%)
Pituitary gland | (9) | (10) | (9) | (10)
Pars distalis, cyst | | 2 (20%) | 1 (11%)
Thyroid gland | (10) | (10) | (10) | (10)
Follicle, degeneration | 2 (20%) | 2 (20%) | 2 (20%) | 2 (20%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Degeneration | 3 (30%) | 2 (20%) | 1 (10%) | 1 (10%)
Preputial gland | (1)
Duct, ectasia | 1 (100%)
Testes | (10) | (10) | (10) | (10)
Cyst | 3 (30%) | 1 (10%) | 1 (10%)
Germinal epithelium, degeneration | 3 (30%) | 2 (20%) | 1 (10%) | 8 (80%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | | 3 (30%) | 1 (10%) | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%)
Thymus | (9) | (10) | (10) | (9)
Atrophy | | 3 (30%) | 1 (10%) | 4 (44%)
Cyst | 3 (33%) | 4 (40%) | 2 (20%) | 3 (33%)
Thymocyte, necrosis | | | 1 (10%) | 1 (11%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Cyst epithelial inclusion | | | 1 (10%)
Hyperplasia | | | 1 (10%) | 1 (10%)
Inflammation, chronic active | | | | 2 (20%)
Epidermis, hyperplasia, focal | 3 (30%) | 1 (10%)
Sebaceous gland, cyst | | 1 (10%)
Site of application, dermis, inflammation, chronic active | | | | 1 (10%)
Site of application, epidermis, hyperkeratosis | 2 (20%) | 8 (80%) | 9 (90%) | 10 (100%)
Site of application, epidermis, hyperplasia | | | 8 (80%) | 9 (90%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar epithelium, hyperplasia | | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | | 1 (10%)
Infiltration cellular, plasma cell | | 1 (10%)
Mineralization | 2 (20%)
Nephropathy | 2 (20%) | 7 (70%) | 7 (70%) | 8 (80%)
Glomerulus, inflammation, membranoproliferative | 1 (10%)
Renal tubule, dilatation | 1 (10%) | 4 (40%) | 4 (40%) | 4 (40%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 2 | 3 | 2 | 2
Natural deaths | | 2 | 2
Survivors
Terminal sacrifice | 8 | 5 | 6 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Salivary glands | | (1) | (1)
Carcinoma | | 1 (100%) | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 3 (30%) | | 1 (10%)
Squamous cell papilloma, multiple | 4 (40%) | 5 (50%) | 5 (50%) | 6 (60%)
Tooth | (4) | (2) | (3) | (3)
Odontogenic tumor | 4 (100%) | 2 (100%) | 3 (100%) | 1 (33%)
Odontogenic tumor, multiple | | | | 1 (33%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (9) | (10)
Genital System
Ovary | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | (9) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Squamous cell carcinoma | 1 (10%)
Squamous cell papilloma | 2 (20%) | 3 (30%) | 1 (10%) | 3 (30%)
Squamous cell papilloma, multiple | 5 (50%) | 2 (20%) | 4 (40%) | 4 (40%)
Site of application, squamous cell papilloma | | | | 3 (30%)
Site of application, squamous cell papilloma, multiple | | | | 3 (30%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | 1 (10%) | 2 (20%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Lymphoma malignant | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 8 | 9 | 9
Total primary neoplasms | 19 | 16 | 16 | 24
Total animals with benign neoplasms | 8 | 8 | 6 | 9
Total benign neoplasms | 13 | 13 | 11 | 22
Total animals with malignant neoplasms | 2 | 1 | 2
Total malignant neoplasms | 2 | 1 | 2
Total animals with uncertain neoplasms-benign or malignant | 4 | 2 | 3 | 2
Total uncertain neoplasms | 4 | 2 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Dichloroacetic Acid^a^

| Vehicle Control | 31.25 mg/kg | 125 mg/kg | 500 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 2 | 3 | 2 | 2
Natural deaths | | 2 | 2
Survivors
Terminal sacrifice | 8 | 5 | 6 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Inflammation, chronic active | 9 (90%) | 9 (90%) | 8 (80%) | 10 (100%)
Hepatocyte, necrosis | 2 (20%) | 1 (10%) | | 5 (50%)
Hepatocyte, vacuolization cytoplasmic | 7 (70%) | 6 (60%) | 8 (80%) | 10 (100%)
Salivary glands | | (1) | (1)
Degeneration | | 1 (100%)
Tooth | (4) | (2) | (3) | (3)
Inflammation, chronic | | | | 1 (33%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | 3 (30%) | | 2 (20%)
Mineralization | 3 (30%) | 1 (10%) | 2 (20%)
Subcapsular, hyperplasia | 7 (70%) | 6 (60%) | 8 (80%) | 5 (50%)
Pituitary gland | (10) | (10) | (9) | (10)
Pars distalis, cyst | 1 (10%) | 2 (20%) | 2 (22%)
Thyroid gland | (10) | (10) | (10) | (10)
Follicle, degeneration | 2 (20%) | 6 (60%) | 2 (20%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 1 (10%) | 1 (10%) | 2 (20%)
Uterus | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%)
Endometrium, hyperplasia, cystic | 9 (90%) | 8 (80%) | 8 (80%) | 8 (80%)
Hematopoietic System
Lymph node, mandibular | (10) | (9) | (10) | (10)
Hyperplasia, lymphoid | 2 (20%) | 3 (33%) | 3 (30%) | 2 (20%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | | 1 (10%)
Thymus | (10) | (10) | (9) | (10)
Atrophy | 3 (30%) | 3 (30%) | 2 (22%) | 1 (10%)
Cyst | 5 (50%) | 2 (20%) | 2 (22%) | 3 (30%)
Thymocyte, necrosis | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Fibrosis | | | 1 (10%)
Hyperkeratosis | | | 1 (10%)
Inflammation, chronic active | | | 3 (30%)
Ulcer | | | 2 (20%)
Epidermis, hyperplasia, focal | | 1 (10%) | 2 (20%)
Site of application, epidermis, hyperkeratosis | 5 (50%) | 8 (80%) | 9 (90%) | 10 (100%)
Site of application, epidermis, hyperplasia | | | 3 (30%) | 6 (60%)
Site of application, epidermis, inflammation, chronic active | | | 1 (10%)
Nervous System
Spinal cord | | | | (1)
Necrosis | | | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation, chronic active | 2 (20%)
Alveolar epithelium, hyperplasia | | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy | 4 (40%) | 2 (20%) | 3 (30%) | 2 (20%)
Glomerulus, inflammation, membranoproliferative | 1 (10%)
Renal tubule, dilatation | 1 (10%) | 2 (20%) | 1 (10%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion