# REFERENCES

The Aldrich Library of ^13^C and ^1^H FT-NMR Spectra (1993). 1st ed., p. 1412(C). Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Vol. 1, p. 876 (A). Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of Infrared Spectra (1981). 3rd ed. (C.J. Pouchert, Ed.), Vol. 1, spectrum 524C (1). Aldrich Chemical Co., Inc., Milwaukee, WI.
Aldrich Technical Information Bulletin No. AL-168: 1,3-Diisopropylcarbodiimide (DIC) (1988). Aldrich Chemical Co., Inc., Milwaukee, WI
Anonymous (1977). Spectrosc. Lett. 10, 959–970.
Azzi, A., Casey, R.P., and Nalecz, M.J. (1984). The effect of N,N’-dicyclohexylcarbodiimide on enzymes of bioenergetic relevance. Biochim. Biophys. Acta 768, 209–226.6095905
Bates, H.S., Jones, J.H., Ramage, W.I., and Witty, M. (1981). Some observations on the activation of alkoxycarbonylamino acids by diisopropylcarbodiimide. In Peptides, Proceedings of the 16th European Peptide Symposium (K. Brunfeldt, Ed.), pp. 185–190.
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Buckles, L.C., and Lewis, S.M. (1977). S-(2-Diisopropylamino-ethyl)-O-ethyl methylphosphonothioate stabilized with soluble carbodiimides. U.S. Patent No. 4012464.
Budnick, E.G. (1968). Triarylarsines as catalysts for converting isocyanates to carbodiimides. U.S. Patent No. 3406198.
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Chadwick, D.H., and Cleveland, T.H. (1979). Isocyanates, Organic. In Kirk-Othmer Encyclopedia of Chemical Technology, 3rd ed. (M. Grayson, D. Eckroth, H.F. Mark, D.F. Othmer, C.G. Overberger, and G.T. Seaborg, Eds.), Vol. 13, pp. 797–799. John Wiley and Sons, New York.
Chhabra, R.S., Bucher, J.R., Wolfe, M., and Portier, C. (2003). Toxicity characterization of environmental chemicals by the U.S. National Toxicology Program: An overview. Int. J. Hyg. Environ. Health 206, 437–445.12971699
Code of Federal Regulations (CFR) 21, Part 58.
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Ellis, H.V. (1991). Treatment for eye irritants. Chem. Eng. News 69, 2.
Furumoto, S. (1971a). Novel method for the synthesis of carbodiimide. Nippon Kagaku Zasshi 92, 357–360.
Furumoto, S. (1971b). Novel method for the synthesis of carbodiimide. Nippon Kagaku Zasshi 92, 1005–1007.
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Harris, C.C. (1996a). Structure and function of the p53 tumor suppresor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 tumor suppressor gene: From the basic research laboratory to the clinic—an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture – molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Izdebski, J., and Pelka, J. (1984). Peptide synthesis using disubstituted carbodiimides which form dichloromethane-soluble urea derivatives. In Peptides, Proceedings of the 18th European Peptide Symposium, (U. Ragnarsson, Ed.) pp. 113–116.
The Janssen Chimica Catalog Handbook of Fine Chemicals for Research and Industry 1991-1992 (1990). p. 457, Janssen Chemica or Spectrum Chemical Manufacturing Corp., Research Triangle Park, NC.
Kricheldorf, H.R., Au, M., and Mang, T. (1985). Models of molecular evolution. 2. Stereospecificity of dipeptide syntheses by means of cyanamides and carbodiimides. Int. J. Pept. Protein Res. 2, 149–157.
Kuney, J.H., Ed. (1990). Chemcyclopedia 91: The Manual of Commercially Available Chemicals, p. 409. American Chemical Society, Washington, DC.
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Miller, M.J. (1980). Isourea-mediated preparation of dehydro amino acids. J. Org. Chem. 45, 3131–3132.
Minnema, L., and Van der Zande, J.M. (1988). Pattern generation in polyimide coatings and its application in an electrophoretic image display. Polym. Eng. Sci. 28, 815–822.
Moore, J.S., and Stupp, S.I. (1990). Room temperature polyesterification. Macromolecules 23, 65–70.
Morita, T., Asano, N., Awogi, T., Sasaki, Y.F., Sato, S., Shimada, H., Sutou, S., Suzuki, T., Wakata, A., Sofuni, T., and Hayashi, M. (1997). Evaluation of the rodent micronucleus assay in the screening of IARC cacinogens (groups 1, 2A and 2B) the summary report of the 6th collaborative study by CSGMT/JEMS MMS. Collaborative Study of the Micronucleus Group Test. Mammalian Mutagenicity Study Group. Mutat. Res. 389, 3–122 (Erratum, 1997, 391, 259–267).9062586
Moyer, R.C. (1990). A carbodiimide eye irritant. Chem. Eng. News 68, 2.
Murphy, A.J. (1981). Kinetics of the inactivation of the ATPase of sarcoplasmic reticulum by dicyclohexylcarbodiimide. J. Biol. Chem. 256, 12,046–12,050.7451430
Nasr, M.L., Goldman, M., Klein, A.K., and Dacre, J.C. (1988). SCE induction in Chinese hamster ovary cells (CHO) exposed to G agents. Mutat. Res. 204, 649–654.3352646
National Institute of Standards Technology (NIST) (1995). Finnigan MAT^TM^ NIST^TM^ Library for GCQ/ICIS.
National Toxicology Program (NTP) (2007). Toxicology and Carcinogenesis Studies of Diisopropylcarbodiimide (CAS No. 693-13-0) in F344/N Rats and B6C3F_1_ Mice (Dermal Studies). Technical Report No. 523, NIH Publication No. 07-4473. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Nutt, R.F. (1978). Cyclization of peptides; reaction of an oligopeptide with isopropylcarbodiimide bound to polystyrene. U.S. Patent No. 4102877.
Ojima, I., Inaba, S., and Nagai, Y. (1974). Syntheses of N-silylformamidines by the hydrosilylation of carbodiimides. Organometal. Chem. 72, C11–C13.
Orlowska, A., Holodowicz, E., and Drabarek, S. (1983). Comparison of dicyclohexylcarbodiimide and diisopropylcarbodiimide as coupling reagents in solid phase peptide syntheses. Pol. J. Chem. 56, 1067–1070.
Paxton, R.J., Jakowatz, J.G., Beatty, J.D., Beatty, B.G., Vlahos, W.G., Williams, L.E., Clark, B.R., and Shively, J.E. (1985). High-specific-activity ^lll^In-labeled anticarcinoembryonic antigen monoclonal antibody: Improved method for the synthesis of diethylenetriaminepentaacetic acid conjugates. Cancer Res. 45, 5694–5699.4053042
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Registry of Toxic Effects of Chemical Substances (RTECS) [database online] (1991a). Cyanamide. Bethesda, MD: National Institute for Occupational Safety and Health; 1971 to present. Updated quarterly. Available from the National Library of Medicine, Bethesda, MD.
Registry of Toxic Effects of Chemical Substances (RTECS) [database online] (1991b). Carbodiimide, diisopropyl. Bethesda, MD: National Institute for Occupational Safety and Health; 1971 to present. Updated quarterly. Available from the National Library of Medicine, Bethesda, MD.
Sabatier, J.M., Tessier-Rochat, M., Granier, C., Van Rietschoten, J., Pedroso, E., Grandas, A., Albericio, F., and Giralt, E. (1987). Convergent solid phase peptide synthesis. VI. Synthesis by the FMOC procedure with a modified protocol of two protected segments, sequence 5-17 and 18-31 of the neurotoxin II of the scorpion Androctonus australis Hector. Tetrahedron 43, 5973–5980.
Satre, M., Lunardi, J., Pougeois, R., and Vignais, P.V. (1979). Inactivation of Escherichia coli BF1-ATPase by dicyclohexylcarbodiimide. Chemical modification of the beta-subunit. Biochemistry 18, 3134–3140.37896
Smeltz, K.C. (1969). Catalysts for preparing carbodiimides. U.S. Patent No. 3426025.
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG.AC) carrying a v-HA-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
White, G.T., and Mullin, K.B. (1967). Diisopropylcarbodiimide. U.S. Patent No. 3352908.
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Witt, K.L., Tice, R.R., Shelby, M.D., Chhabra, R.S., and Zeiger, E. (1999). Induction of micronucleated erythrocytes in rodents by diisopropylcarbodiimide and dicyclohexylcarbodiimide: Dependence on exposure protocol. Environ. Mol. Mutagen. 33, 65–74.10037325
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-HA-ras (TG.AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Wyde, M.E., Braen, A.P.J.M., Hejtmancik, M., Johnson, J.D., Toft, J.D., Blake, J.C., Cooper, S.D., Mahler, J., Vallant, M., Bucher, J.R., and Walker, N.J. (2004). Oral and dermal exposure to 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) induces cutaneous papillomas and squamous cell carcinomas in female hemizygous Tg.AC transgenic mice. Toxicol. Sci. 82, 34–45.15282402
Zeiger, E. (1998). Identification of rodent carcinogens and noncarcinogens using genetic toxicity tests: Premises, promises, and performance. Regul. Toxicol. Pharmacol. 2, 85–95.