# RESULTS

## Mice 20-Week Study

There were no deaths considered related to diisopropylcarbodiimide administration. Twelve animals died or were sacrificed moribund prior to the end of the study; two each from the vehicle control, 4.38, 8.75, and 17.5 mg/kg groups, and four from the 35 mg/kg group (Table 2). There were no treatment-related clinical findings that contributed to the morbidity/mortality of these animals. The most consistent incidental finding was odontoma (odontogenic tumor), which occurred without a dose relationship in animals from vehicle control and several dose groups. Odontogenic tumors are spontaneous neoplasms in Tg.AC mice with a reported incidence of 17.3% in control female Tg.AC hemizygous mice at 33 weeks of age (Mahler et al., 1998). They arise in the mandible or maxilla from primitive tooth structures resulting in progressive malformation of the jaw, malocclusion and difficulty in eating with loss of body condition. All other animals survived to the end of the study. Of the surviving animals, mean body weights were similar to those of vehicle controls (Table 2 and Figure 1). There were no significant differences in organ weights between dosed groups and the vehicle control group (Table C1).

No neoplasms or nonneoplastic lesions were observed in female Tg.AC hemizygous mice that were considered related to administration of diisopropylcarbodiimide, including in the skin at the site of application. In the forestomach, single squamous cell papillomas occurred in two of 10 animals macroscopically examined from each of the 8.75, 17.5, and 70 mg/kg groups. Although this is slightly higher than the reported background incidence of 10.3% in control female Tg.AC hemizygous mice (Mahler et al., 1998), there was no dose-related increase in the number or multiplicity of tumors, and they were considered unrelated to administration of diisopropylcarbodiimide.

TABLE 2 Survival and Body Weights of Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Diisopropylcarbodiimide

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
0 | 8/10^c^ | 20.9 ± 0.5 | 27.8 ± 0.5 | 7.1 ± 0.6
4.38 | 8/10^d^ | 20.7 ± 0.4 | 29.1 ± 1.6 | 7.8 ± 1.5 | 105
8.75 | 8/10^e^ | 21.1 ± 0.4 | 30.0 ± 2.7 | 8.9 ± 2.4 | 108
17.5 | 8/10^f^ | 21.5 ± 0.6 | 26.9 ± 1.0 | 5.3 ± 0.8 | 97
35 | 6/10^g^ | 20.3 ± 0.4 | 26.0 ± 1.4 | 5.7 ± 1.4 | 94
70 | 10/10 | 20.6 ± 0.4 | 25.6 ± 0.5 | 5.0 ± 0.5 | 92

a Number of animals surviving at 20 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the vehicle control group are not significant by Dunnett’s test.

c Week of death: 14, 16

d Week of death: 14, 20

e Week of death: 15, 19

f Week of death: 12, 16

g Week of death: 7, 7, 8, 10

FIGURE 1 Growth Curves for Female Tg.AG Hemizygous Mice Dermally Administered Diisopropylcarbodiimide for 20 Weeks

## 27-Week Study

All animals survived to the end of the study (Table 3). Mean body weights of the dosed groups were similar to that of the vehicle control group (Table 3 and Figure 2). There were no clinical findings related to diisopropylcarbodiimide administration. There were no treatment-related gross lesions.

Epidermal hyperplasia of the skin occurred at the site of application in 8 of 15 mice receiving 70 mg/kg while none were seen in any other dose groups or controls (Table B2). Epidermal hyperplasia was of minimal severity and focal to multifocal in six animals; one had mild hyperplasia, and one had moderate hyperplasia. The moderate hyperplasia was a more extensive/diffuse change. Epidermal hyperplasia was characterized as an increase in epidermal thickness from the normal one or two cells up to three cells thick (minimal hyperplasia), four cells thick (mild hyperplasia), or five cells thick (moderate hyperplasia). No neoplasms were observed in female p53 haploinsufficient mice that were considered related to administration of diisopropylcarbodiimide.

TABLE 3 Survival and Body Weights of Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Diisopropylcarbodiimide

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
0 | 15/15 | 18.1 ± 0.4 | 32.1 ± 1.7 | 14.0 ± 1.5
4.38 | 15/15 | 17.9 ± 0.4 | 30.9 ± 1.1 | 13.0 ± 0.9 | 96
8.75 | 15/15 | 18.1 ± 0.3 | 32.6 ± 1.1 | 14.5 ± 1.0 | 101
17.5 | 15/15 | 17.7 ± 0.4 | 30.2 ± 1.5 | 12.5 ± 1.3 | 94
35 | 15/15 | 17.9 ± 0.3 | 32.5 ± 1.4 | 14.6 ± 1.2 | 101
70 | 15/15 | 17.8 ± 0.3 | 30.6 ± 1.7 | 12.8 ± 1.6 | 95

a Number of animals surviving at 27 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

FIGURE 2 Growth Curves for Female p53 Haploinsufficient Mice Dermally Administered Diisopropylcarbodiimide for 27 Weeks