# MATERIALS AND METHODS

## Procurement and Characterization

### Diisopropylcarbodiimide

Diisopropylcarbodiimide was obtained from Aldrich Chemical Company (Milwaukee, WI) in two lots. Lot 01207BG was used during the 20-week study; lot 13016JS was used during the 27-week study. Identity and purity analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO) and by the study laboratories at Microbiological Associates, Inc. (Bethesda, MD; 20-week study), and BioReliance Corporation (Rockville, MD; 27-week study); physical properties, moisture content, and stability of the bulk diisopropylcarbodiimide were determined by the analytical chemistry laboratory. Reports on analyses performed in support of the diisopropylcarbodiimide studies are on file at the National Institute of Environmental Health Sciences.

Lot 01207BG, a colorless liquid, was identified as diisopropylcarbodiimide by the study laboratory using infrared (IR) spectroscopy. Lot 13016JS was identified as diisopropylcarbodiimide by the study laboratory using IR spectroscopy and by the analytical chemistry laboratory using IR, proton nuclear magnetic resonance (NMR), and ultraviolet/visible spectroscopy and gas chromatography (GC)/mass spectrometry. All spectra were consistent with the structure of diisopropylcarbodiimide and with literature references.

The purity of lot 01207BG was determined by the study laboratory using GC. The purity of lot 13016JS was determined by the study laboratory using GC and by the analytical chemistry laboratory using thin layer chromatography (TLC) and GC. The moisture content of lot 13016JS was determined by the analytical chemistry laboratory using Karl Fischer titration; the boiling point and relative density of this lot were also measured by the analytical chemistry laboratory.

For lot 01207BG, GC indicated a major peak and five impurity peaks with areas ranging from 0.05% to 0.27% of the total peak area. Fourteen minor impurities were present in the sample chromatograms. The overall purity of lot 01207BG was determined to be 99.35%.

For lot 13016JS, the boiling point and relative density were consistent with the literature value for diisopropylcarbodiimide. Karl Fischer titration indicated 0.06% water in the bulk chemical. TLC detected a major, a minor, and two trace spots. GC at the study laboratory indicated a relative purity of 100.4% when compared to a frozen reference sample. GC indicated a major peak and five impurity peaks with a combined area of approximately 0.5% of the total peak area; the purity of the test article was determined to be approximately 99.5%. The overall purity of lot 13016JS was determined to be greater than 99%.

The analytical chemistry laboratory conducted accelerated stability studies of lot 13016JS with samples stored for 2 weeks in amber vials with Teflon^®^-lined septa at approximately 5°, 25°, and 60° C compared to frozen samples from the same lot stored at −20° C. Analysis using GC indicated that the test article was stable when protected from light at temperatures up to approximately 60° C for 2 weeks. To ensure stability, the bulk chemical was stored at room temperature under nitrogen, protected from light as recommended by the manufacturer. Periodic purity analyses of the bulk chemical were performed during both studies using GC. No degradation of the bulk chemical was detected.

### Anhydrous Ethanol

Anhydrous ethanol was obtained from Pharmco (Brookfield, CT) in one lot (number unknown) used for the 20-week study and two lots (9901074 and 9801193) that were used for the 27-week study. Identity and purity analyses of all lots were conducted by the study laboratories. The chemical, a clear liquid, was identified as ethanol using IR spectroscopy; the sample spectra were a good match for the reference spectrum of ethanol. The purity of each lot was determined using GC. No impurities were detected that exceeded a relative concentration of 0.1% in any lot.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing diisopropylcarbodiimide and anhydrous ethanol to give the required concentrations; formulations were prepared once not more than 7 days prior to the study start and every 3 weeks thereafter for the 20-week study or monthly for the 27-week study. The dose formulations were stored at room temperature for the 20-week study and the 27-week study until April 6, 1999, or later, when formulations were stored at −20° C for up to 35 days.

Because the dose formulations were true solutions of the test article in ethanol, homogeneity studies were not performed. Prior to the 20-week study, a stability study of 2.19 mg/mL dose formulations of lot 01207BG was conducted by the study laboratory using GC; stability was confirmed for up to 35 days for the dose formulation stored at ambient temperature in sealed containers under a nitrogen headspace and for up to 3 hours when exposed to light and air at ambient temperature.

Periodic analyses of the dose formulations of diisopropylcarbodiimide were conducted by the study laboratories using GC. During the 20-week study, the dose formulations were analyzed four times; animal room samples of these dose formulations were also analyzed. All 20 dose formulations analyzed were within 10% of the target concentrations; all 20 of the animal room samples analyzed were within 10% of the target concentrations. Dose formulations were analyzed four times during the 27-week study; animal room samples of these dose formulations were also analyzed. Of the 20 dose formulations analyzed, all were within 10% of the target concentrations; 9 of 20 animal room samples were within 10% of the target concentrations. Unusual degradation was observed in the animal room samples from the formulations prepared on February 17, 1999, and June 7, 1999. Attempts to discover the cause of the degradation in the formulations were not conclusive, but the most likely cause, water in the anhydrous ethanol, was eliminated. To prevent degradation of the test chemical, formulations prepared on or after April 6, 1999, were stored at −20° C.

## 20-Week Study

Female FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the mice were 4 weeks old. Animals were quarantined for 13 days and were 6 weeks old on the first day of the study. Before the study began, five mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood was collected from five randomly selected vehicle control mice at study termination. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b); all results were negative.

The dose levels selected for this study were based on results from a 3-month toxicity study in B6C3F_1_ mice (NTP, 2006). Groups of 10 male and 10 female mice were dermally administered 0, 17.5, 35, 70, 140, or 280 mg/kg diisopropylcarbodiimide 5 days per week for 3 months. All 280 mg/kg males and females and nine 140 mg/kg males and females died before the end of the study. The final body weight gain of 70 mg/kg males was significantly less than that of vehicle controls. At the site of application, there were significant increases in the incidences of epidermal hyperplasia in males and females administered 70 mg/kg or greater, chronic inflammation in 140 and 280 mg/kg males and 70 mg/kg or greater females, and sebaceous gland hyperplasia in 140 mg/kg males. Based on these results, 70 mg/kg was selected as the high dose for the current studies with four lower doses of 35, 17.5, 8.75, and 4.38 mg/kg.

Groups of 10 female mice received dermal applications of 0, 4.38, 8.75, 17.5, 35, or 70 mg/kg in ethanol, 5 days per week for 20 weeks. A dosing volume of 2 mL ethanol per kg body weight was applied to the center of a shaved dorsal area extending from the posterior of the scapulae to the base of the tail, with the application site no greater than 10% of the animal’s body surface. A minimum of two consecutive days of dosing were performed prior to terminal sacrifice, with the last dose within 24 hours of sacrifice. Animals were housed individually, with feed and water available ad libitum. Body weights were recorded initially, weekly, and at the end of the study, and clinical findings were recorded weekly. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, and thymus were weighed. Microscopic examinations were performed on all vehicle control and 70 mg/kg animals and all animals that died early. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Table 1 lists the tissues and organs routinely examined.

## 27-Week Study

Female B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the animals were approximately 5 weeks old. Animals were quarantined for 13 days and were 7 weeks old on the first day of the study. Before initiation of the study, five mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood was collected at study termination from five randomly selected vehicle control mice. The sera were analyzed for antibody titers to rodent viruses; all results were negative.

The dose levels selected for this study were based on results from a 3-month toxicity study in B6C3F_1_ mice (NTP, 2006) as described for the 20-week study. Groups of 15 female mice received dermal applications of 0, 4.38, 8.75, 17.5, 35, or 70 mg/kg in ethanol 5 days per week for 27 weeks. The dosing volume of 2 mL/kg was applied to the center of a shaved dorsal area posterior of the scapulae to the base of the tail, with the application site no greater than 10% of the animal’s body surface. A minimum of two consecutive days of dosing were performed prior to terminal sacrifice, with the last dose given within 24 hours of sacrifice. Mice were housed individually, with feed and water available ad libitum. Body weights were recorded initially, weekly, and at the end of the study, and clinical findings were recorded weekly. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all animals. Histopathologic examinations were performed on all mice. Skin samples from the site of application were cut in an anterior-posterior direction, trimmed or marked with indelible ink to indicate the anterior end, and placed on an index card to keep them flattened during fixation. Control skin samples from an untreated area were also taken. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Table 1 lists the tissues and organs routinely examined.

Upon completion of the laboratory pathologist’s histopathologic evaluation, the slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were sent to an independent pathology laboratory where quality assessment was performed. Results were reviewed and evaluated by the NTP Pathology Working Group (PWG); the final diagnoses represent a consensus of contractor pathologists and the PWG. Details of these review procedures have been described by Maronpot and Boorman (1982) and Boorman et al. (1985).

TABLE 1 Experimental Design and Materials and Methods in the Dermal Studies of Diisopropylcarbodiimide

20-Week Study | 27-Week Study
Study Laboratory
Microbiological Associates, Inc. (Bethesda, MD) | BioReliance Corporation, (Rockville, MD)
Strain and Species
FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice | B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
13 days | 13 days
Average Age When Studies Began
6 weeks | 7 weeks
Date of First Dose
June 14, 1995 | January 4, 1999
Duration of Dosing
20 weeks | 27 weeks
Date of Last Dose
October 31, 1995 | July 6-7, 1999
Necropsy Dates
November 1, 1995 | July 7-8, 1999
Average Age at Necropsy
26 weeks | 34 weeks
Size of Study Groups
10 females | 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 20-week studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
NIH-07 open formula meal/pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Irradiated NTP-2000 open formula meal/pelleted diet (Ziegler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly
Water
Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), rotated every 2 weeks | Polycarbonate (Lab Products, Inc., Seaford, DE), rotated every 2 weeks
Bedding
Sani-chips^®^ (PJ. Murphy Forest Products Corp., Montville, NJ), changed weekly | Same as 20-week study
Cage Filters
Remay 2016 (Snow Filtration, West Chester, OH), changed weekly | Same as 20-week study
Racks
Stainless (Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as 20-week study
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Room air changes: 10/hour | Room air changes: 10/hour
Doses
0, 4.38, 8.75, 17.5, 35, or 70 mg/kg administered in ethanol (2 mL/kg body weight) 5 days per week | 0, 4.38, 8.75, 17.5, 35, or 70 mg/kg administered in ethanol (2 mL/kg body weight) 5 days per week
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, weekly, and at the end of the studies; clinical findings were recorded weekly. | Observed twice daily; animals were weighed initially, weekly, and at the end of the studies; clinical findings were recorded weekly.
Method of Sacrifice
Carbon dioxide asphyxiation | Same as 20-week study
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, and thymus. | Necropsies were performed on all animals.
Histopathology
Complete histopathologic examinations were performed on all vehicle control and 70 mg/kg animals and all animals that died early. In addition to gross lesions and tissue masses the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, gallbladder, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodonum, jejunum, ileum), kidney, liver, lung with mainstream bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, salivary gland, skin (site of application), spleen, stomach (forestomach and glandular), thymus, thyroid gland, trachea, urinary bladder, and uterus. Chemical-related lesions (target organs) were identified and these organs plus gross lesions and tissue masses were examined in the remaining dose groups. | Histopathologic examinations were performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, kidney, liver, lymph nodes (mandibular, mediastinal, and mesenteric), lung and bronchi, mammary gland, ovary, parathyroid gland, pituitary gland, skin (site of application and control site), spleen, stomach (forestomach and glandular), thymus, thyroid gland, trachea, and uterus. Tissues with chemical-related lesions (target organs) were identified in the high dose group and successively lower dose groups were examined until a group with no lesions was reached.

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Tables A1, A2, B1, and B2 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979), a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973).

## Quality Assurance Methods

The 20- and 27-week studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from these studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.