# INTRODUCTION

Diisopropylcarbodiimide

CAS No. 693-13-0

Chemical Formula: C_7_H_14_N_2_ Molecular Weight: 126.20

Synonyms: 1,3-Diisopropylcarodiimide; N,N’-diisopropylcarbodiimide; N,N’-methanetetraylbis (2-propanamine)

## Chemical and Physical Properties

Diisopropylcarbodiimide is a colorless liquid, with a boiling point of 145° to 148° C, a flash point of 33° C (closed cup), a refractive index of 1.433, and a density of 0.806 g/mL (Aldrich, 1988). It is flammable; soluble in chloroform, methylene chloride, acetonitrile, dioxane, dimethylformamide, and tetrahydrofuran; and reacts with water to form 1,3-diisopropylurea. Diisopropylcarbodiimide is a member of the carbodiimide class of chemicals.

Diisopropylcarbodiimide is available in purities ranging from 97% to 99% in quantities up to 1,000 kg. The main impurities are unreacted isocyanates and polymerized carbodiimides (Janssen Chimica, 1990; Kuney, 1990).

## Production, Use, and Human Exposure

Diisopropylcarbodiimide is manufactured primarily by four processes. In the first process, diisopropylcarbodiimide is produced by extended or excessive heating of isopropyl isocyanate from 100° to 250° C under anhydrous conditions to condense the carbodiimide with elimination of carbon dioxide. A number of catalysts are effective in accelerating this reaction to the extent of making it a practical synthesis for this symmetrical carbodiimide. The phospholine oxides are particularly effective catalysts, although simple trialkylphosphine oxides or triethyl phosphate may be used (Chadwick and Cleveland, 1979). Other organometallic catalysts, including tetraisopropyltitanate and tetraisopropylzirconate, are also used to produce diisopropylcarbodiimide (Budnick, 1968; Smeltz, 1969).

In a second process, N,N’-diisopropylthiourea is reacted with cyanuric chloride in dichloromethane to yield an oily product, which, when hydrolyzed with sodium hydroxide and heated, yields diisopropylcarbodiimide and trithiocyanuric acid (Furumoto, 1971a). Thirdly, diisopropylcarbodiimide can be obtained by treating N,N’-diisopropylthiourea in dichloromethane with dichlorodicyanobenzoquinone; the resultant mixture is evaporated and heated in sodium hydroxide to yield diisopropylcarbodiimide (Furumoto, 1971b). In a fourth process patented by Celanese Corporation in 1967, a reaction mass consisting of diisopropylthiourea, lead oxide, and water is heated to refluxing temperature, the mixture is distilled, and diisopropylcarbodiimide is separated by decantation (White and Mullin, 1967).

Although carbodiimides were discovered in 1873, it was not until the early 1950s that they were used in industry. Reactivity of these compounds with free carboxyl groups made them valuable as stabilizing agents in elastomers, natural rubber, and many types of polyolefins, polyesters, resins, fibers, cellulose esters, and foam materials to protect against deterioration. In 1953, it was discovered that carbodiimides are potent condensing agents for mono- and diesters of phosphoric acid and for the corresponding di- and tetraesters of pyrophosphoric acid. Since then, these chemicals have been widely used in the synthesis of ortho- and pyrophosphate esters, nucleotides, cyclic phosphates, oligoribonucleotides, polynucleotides, nucleoside-5’-phosphoroamidates, and mixed anhydrides (Azzi et al., 1984).

Diisopropylcarbodiimide is a useful reagent for peptide syntheses, especially solid-phase peptide synthesis. For example, diisopropylcarbodiimide is used as a peptide coupling reagent in the synthesis of protected peptide proteins of scorpion neurotoxin II, the N-hydroxysuccin-amide active ester of diethylenetriaminepentaacetic acid (DTPA) (which is subsequently used in a process for conjugating DTPA to proteins), N-acyl ureas, and 2-alkoxyoxazolones from alkoxycarbonylamino acids and as a condensing reagent in dipeptide synthesis (Bates et al., 1981; Orlowska et al., 1983; Izdebski and Pelka, 1984; Kricheldorf et al., 1985; Paxton et al., 1985; Sabatier et al., 1987). In addition, diisopropylcarbodiimide is used as a chemical intermediate in the synthesis of N-silylformamides (Ojima et al., 1974) and in the preparation of polyimide precursor coatings for electrophoretic image display fabrication (Minnema and Van der Zande, 1988).

There are numerous other proposed uses for diisopropylcarbodiimide. It has been reported that insoluble resin-bound diisopropylcarbodiimide, in the presence of 1-hydroxybenzotriazole, catalyzed the synthesis of the cyclic peptide gramicidin S (Nutt, 1978). Also, alpha, beta-dehydroamino acid derivatives can be made from serine, threonine, or cysteine using diisopropylcarbodiimide (Miller, 1980). Diisopropylcarbodiimide has been used as a stabilization reagent for a solution of S-(diisopropylaminoethyl)-O-ethyl methylphosphonothioate (Buckles and Lewis, 1977). In organic synthesis, diisopropylcarbodiimide has been used in cycloaddition reactions to form a number of heterocyclic compounds (Aldrich, 1988). Like most carbodiimides, diisopropylcarbodiimide has also been used in dehydration reactions for conjugated alkadienoic acid and anhydride preparations. In the presence of (dimethylamino)pyridinium toluenesulfonate as a catalyst, diisopropylcarbodiimide has been used to prepare polyester from hydroxyphenyl-terminated carboxylic acids (Moore and Stupp, 1990). Diisopropylcarbodiimide is used as a stabilizer for the military nerve agent Sarin (Nasr et al., 1988).

Human exposure to diisopropylcarbodiimide could occur during the extensive handling of the compound that occurs during the synthesis of peptides and other compounds in the chemical, pharmaceutical, and recombinant DNA industries.

## Absorption, Distribution, Metabolism, and Excretion

NTP conducted absorption and distribution studies via the dermal route in mice and rats (NTP, 2006). Data indicated that only approximately 1% to 2% of the radiolabeled dose was absorbed due to the high volatility of diisopropylcarbodiimide. The majority of the dose was recovered in the charcoal-impregnated appliances used to cover the site of application. Approximately 90.7% of the dose was unabsorbed and 90.5% was contained in the appliance and skin wash. Less than 0.2% of the administered dose was recovered from any tissue site. The majority of the dose rapidly volatilized from the dose site and was not available for absorption.

## Toxicity

### Experimental Animals

The oral LD_50_ for diisopropylcarbodiimide in mice is 36 mg/kg (RTECS, 1991a). While the chemistry of diisopropylcarbodiimide and dicyclohexylcarbodiimide are virtually identical, interactions with biomolecules differ. Two cases in point involve ATPase. The Ca^2+^- ATPase of sarcoplasmic reticulum vesicles is readily inactivated by diisopropylcarbodiimide (Murphy, 1981). Although the related chemical, dicyclohexylcarbodiimide, readily inactivates Escherichia coli BF1-ATPase at 0.05 mM, diisopropylcarbodiimide shows almost no inactivation at this concentration (Satre et al., 1979).

The National Toxicology Program (NTP, 2006) conducted 2-week and 3-month dermal studies of diisopropylcarbodiimide in male and female F344/N rats and B6C3F_1_ mice. In the 2-week studies, rats and mice were administered 0, 3, 9, 27, 81, or 242 mg or 0, 1, 3, 9, 27, or 81 mg diisopropylcarbodiimide per animal, respectively. All rats administered 27 mg or greater and all mice administered 9 mg or greater died before the end of the studies. Nonneoplastic lesions were observed at the site of application in dosed animals. In the 3-month studies, rats were administered 0, 10, 20, 40, 80, or 160 mg/kg, and mice were administered 0, 17.5, 35, 70, 140, or 280 mg/kg. All rats administered 160 or 80 mg/kg, all mice administered 280 mg/kg, and most mice administered 140 mg/kg died early. Nonneoplastic lesions were observed at the site of application and in the brain, lung, and liver of rats and at the site of application and in the thymus of mice. No chemical-related changes in hematology or clinical chemistry parameters were reported in rats or mice.

### Humans

Delayed, temporary blindness was reported in a worker following an acute occupational exposure to diisopropylcarbodiimide vapor (Moyer, 1990). The worker had cleaned up a 1 L spill of diisopropylcarbodiimide while wearing a respirator, laboratory coat, and impervious gloves. Approximately 12 to 18 hours later, the worker experienced hazy vision followed by mild pain that maximized 34 hours after the exposure. Damage to the outer layer of the cornea resulted in blindness that subsided over a 2-week period. Ellis (1991) noted that this injury resembled mild to moderate mustard gas injury, for which the postulated mechanism of action is alkylation of nucleophilic functional groups of intracellular components, occurring within minutes of exposure and leading to cellular dysfunction and even cell death. This author noted that it is reasonable to assume that all alkyl-carbodiimides are capable of functioning as alkylating agents and are therefore potential vesicants and carcinogens.

## Reproductive and Developmental Toxicity

### Experimental Animals

No chemical-related differences in reproductive parameters were observed in F344/N rats administered 0, 10, 20, 40, 80, or 160 mg/kg or B6C3F_1_ mice administered 0, 17.5, 35, 70, 140, or 280 mg/kg in 3-month dermal studies (NTP, 2006). No other information on the reproductive or developmental toxicity of diisopropylcarbodiimide in animals was found in the literature.

A single oral reproductive study in rats of the related chemical carbodiimide has been reported (RTECS, 1991b). In this study, a dose of 2,450 mg carbodiimide/kg caused preimplantation mortality, 1,750 mg/kg caused paternal effects (testes, epididymis, sperm duct, prostate, seminal vesicle, Cowper’s gland, and accessory glands), 208 mg/kg affected postimplantation mortality and the live birth index. In the same study, 2,600 mg/kg affected live birth index and growth statistics in newborn rats.

### Humans

No information on the reproductive or developmental toxicity of diisopropylcarbodiimide in humans was found in the literature.

## Carcinogenicity

### Experimental Animals

In 2-year dermal studies of diisopropylcarbodiimide conducted by the NTP (2006), male and female F344/N rats and B6C3F_1_ mice were administered 0, 10, 20, or 40 mg/kg. No neoplastic effects occurred in either rats or mice. Because of severe neurological signs exhibited by 40 mg/kg male rats, a neuropathological review of these animals was performed, which revealed neuronal necrosis, cerebral hemorrhage, and/or fibrinoid vascular necrosis of the brain, and spinal axonopathy was also present. Other chemical-related nonneoplastic lesions in rats included hemorrhage in the lung of males and chronic lung inflammation and alveolar epithelium hyperplasia in females; at the site of application, epidermal hyperplasia and chronic inflammation occurred in males and females. In male mice, epidermal hyperplasia and focal dermal inflammation occurred at the site of application.

### Humans

No epidemiology studies or case reports associating diisopropylcarbodiimide exposure with cancer risk in humans were found in the literature.

## Genetic Toxicity

Diisopropylcarbodiimide was not mutagenic in Salmonella typhimurium strains TA97, TA98, TA100, or TA1535 with or without induced rat or hamster liver S9 activation enzymes when tested at 3 to 1,000 µg/plate (NTP, 2006). Witt et al. (1999) described the results of a series of in vivo mutagenicity tests with diisopropylcarbodiimide. The chemical was shown to induce micronuclei in erythrocytes of male and female mice treated by skin painting for a period of 3 months. An additional subchronic micronucleus investigation was performed with diisopropylcarbodiimide in male mice, in which the chemical was administered by skin painting for 4 months and weekly or biweekly counts of micro-nucleated erythrocytes, as well as percent polychromatic erythrocytes (% PCEs), were obtained. Results of this study confirmed the activity of diisopropylcarbodiimide that was observed in the 3-month skin painting study. However, short-term tests using a three-injection protocol with diisopropylcarbodiimide in rats and in mice showed no evidence of micronucleus induction in bone marrow PCEs. Results of a single-injection mouse micronucleus test with diisopropylcarbodiimide gave results that were concluded to be equivocal; frequencies of micronucleated PCEs were significantly increased in peripheral blood samples obtained 48 hours after injection, but in bone marrow, the frequency of micro-nucleated PCEs, although elevated at 24 and 48 hours in two of three trials, did not differ significantly from the control levels. The authors suggested that one interpretation of these results might be that diisopropylcarbodiimide induces chromosomal damage in erythrocytes soon after treatment, and that, due to the kinetics of erythrocyte maturation, this damage is detectable as micronucleated cells in blood but not bone marrow at the standard time points assayed for micronucleus induction. Alternatively, the spleen might be a target organ for diisopropylcarbodiimide, and damage to splenic cells might result in increased frequencies of micronucleated erythrocytes in the circulating erythrocyte population compared to the population of erythrocytes residing in the bone marrow.

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, two genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53) or a gain of oncogene function (Ha-ras) were used to determine how these animals would respond to diisopropylcarbodiimide exposure. The Tg.AC hemizygous and p53 haploinsufficient mice have been shown to be susceptible to the rapid development of cancer and are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) and the NTP as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996; Pritchard et al., 2003).

### FVB/N-TgN(v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

The Tg.AC hemizygous mouse (on an FVB/N background) was developed by Leder et al. (1990) by introduction via pronuclear injection of a tripartite transgene composed of the promotor of the mouse embryonic zeta-globin gene, through the v-Ha-ras coding sequence, with point mutations in codons 12 and 59, and an SV40 polyadenylation sequence.

The Tg.AC hemizygous transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). The Tg.AC strain of mice is hemizygous for a mutant v-Ha-ras transgene. The model was developed by Leder et al. (1990) with an inducible zeta-globin promoter driving the expression of a mutated v-Ha-ras oncogene and is regarded as a genetically initiated model. With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is usually transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC hemizygous mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumor responses in the skin of Tg.AC hemizygous mice and lead to squamous cell papillomas and/or carcinomas of the forestomach (Wyde et al., 2004). To date, the appearance of either spontaneous or induced tumors has been shown to involve transgene expression. However, the mechanism of response by the Tg.AC hemizygous model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Cutaneous papillomas at various sites have been reported at 10% and 7% incidence in 33-week-old control male and female Tg.AC hemizygous mice, respectively (Mahler et al., 1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice can develop odontogenic tumors as early as 33 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at an incidence of greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar-bronchiolar adenomas, salivary gland duct carcinomas, and erythro-leukemia (Mahler et al., 1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current Report for studies of diisopropylcarbodiimide because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard et al., 2003).

### B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient Mouse Model

The heterozygous B6.129-Trp53 (N12)^tmlBrd(+/−)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein has a short half-life and exists at a very low concentration under normal cell physiological conditions. However, in DNA damaged cells that are able to replicate, p53 is expressed in high amounts with a significant increase in half-life due to posttranslational modification (phosphorylation or acetylation). Mutations in p53 may also increase the protein half-life and alter functions that may contribute to transformation and development of the malignant phenotype. The p53 protein is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues in different p53 domains may be phosphorylated or acetylated, which may determine specific p53 functions. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site, and hence are unable to function as tumor suppressors, frequently occur in human cancers. Alterations of the Trp53 gene occur not only as somatic mutations in human malignancies, but also as germline mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/–) has only a single functional wild-type p53 allele, which provides a target for mutagens. The p53 protein has a short half-life and exists at a very low concentration under normal cell physiological conditions. However, in DNA damaged cells that are able to replicate, p53 is expressed in high amounts with a significant increase in half-life due to posttranslational modification (phosphorylation or acetylation). Mutations in p53 may also increase the protein half-life and alter functions that may contribute to transformation and development of the malignant phenotype. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c). Many amino acid residues in different p53 domains may be phosphorylated or acetylated, which may determine specific p53 functions.

Heterozygous p53^(+/−)^ mice develop normally, and like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency.

## Study Rationale

Diisopropylcarbodiimide and dicyclohexylcarbodiimide were nominated by the National Cancer Institute for toxicity and carcinogenicity studies as representatives of the carbodiimide chemical class. The results of the dicyclohexylcarbodiimide studies will be presented in separate reports.

In the studies presented in this Report, the dermal route of exposure was chosen to mimic the primary route of human exposure. The studies in Tg.AC hemizygous and p53 haploinsufficient genetically modified mouse models were performed as part of the NTP effort to evaluate alternative test models that require shorter exposure times, are less expensive to study, and use fewer animals when compared to the traditional 2-year study design.

The NTP has completed 2-year carcinogenicity studies of diisopropylcarbodiimide in rats and mice. The results of those studies have been reported in a separate Technical Report (NTP, 2006).