# APPENDIX D CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Diisopropylcarbodiimide

Diisopropylcarbodiimide was obtained from Aldrich Chemical Company (Milwaukee, WI) in two lots. Lot 01207BG was used during the 20-week studies; lot 13016JS was used during the 27-week studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO) and by the study laboratories at Microbiological Associates, Inc. (Bethesda, MD; 20-week study), and BioReliance Corporation (Rockville, MD; 27-week study); physical properties, moisture content, and stability of the bulk diisopropylcarbodiimide were determined by the analytical chemistry laboratory. Reports on analyses performed in support of the diisopropylcarbodiimide studies are on file at the National Institute of Environmental Health Sciences.

Lot 01207BG, a colorless liquid, was identified as diisopropylcarbodiimide by the study laboratory using infrared (IR) spectroscopy. Lot 13016JS was identified as diisopropylcarbodiimide by the study laboratory using IR spectroscopy and by the analytical chemistry laboratory using IR, proton nuclear magnetic resonance (NMR), and ultraviolet/visible spectroscopy and gas chromatography (GC)/mass spectrometry by system A (Table D1). All spectra were consistent with the structure of diisopropylcarbodiimide and with literature references (Anonymous, 1977; Aldrich 1981, 1985, 1993; NIST, 1995). Representative IR and proton NMR spectra are presented in Figures D1 and D2.

The purity of lot 01207BG was determined by the study laboratory using GC system B. The purity of lot 13016JS was determined by the study laboratory using GC system C and by the analytical chemistry laboratory using thin layer chromatography (TLC) and GC system D. The moisture content of lot 13016JS was determined by the analytical chemistry laboratory using Karl Fischer titration; the boiling point and relative density of this lot were also measured by the analytical chemistry laboratory.

For lot 01207BG, GC by system B indicated a major peak and five impurity peaks with areas ranging from 0.05% to 0.27% of the total peak area. Fourteen minor impurities were present in the sample chromatograms. The overall purity of lot 01207BG was determined to be 99.35%.

For lot 13016JS, the boiling point and relative density were consistent with the literature value for diisopropylcarbodiimide (Aldrich, 1988). Karl Fischer titration indicated 0.06% water in the bulk chemical. TLC detected a major, a minor, and two trace spots. GC by system C indicated a relative purity of 100.4% when compared to a frozen reference sample from the analytical chemistry laboratory. GC by system D indicated a major peak and five impurity peaks with a combined area of approximately 0.5% of the total peak area; the purity of the test article was determined to be approximately 99.5%. The overall purity of lot 13016JS was determined to be greater than 99%.

The analytical chemistry laboratory conducted accelerated stability studies of lot 13016JS with samples stored for 2 weeks in amber vials with Teflon^®^-lined septa at approximately 5°, 25°, and 60° C compared to frozen samples from the same lot stored at −20° C. Analysis using GC system E indicated that the test article was stable when protected from light at temperatures up to approximately 60° C for 2 weeks. To ensure stability, the bulk chemical was stored at room temperature under nitrogen, protected from light as recommended by the manufacturer. Periodic purity analyses of the bulk chemical were performed during both studies using GC by system B. No degradation of the bulk chemical was detected.

### Anhydrous Ethanol

Anhydrous ethanol was obtained from Pharmco (Brookfield, CT) in one lot (number unknown) used for the 20-week study and two lots (9901074 and 9801193) that were used for the 27-week study. Identity and purity analyses of all lots were conducted by the study laboratories. The chemical, a clear liquid, was identified as ethanol using IR spectroscopy; the sample spectra were a good match for the reference spectrum of ethanol (Aldrich, 1985). The purity of each lot was determined using GC by system F. No impurities were detected that exceeded a relative concentration of 0.1% in any lot.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing diisopropylcarbodiimide and anhydrous ethanol to give the required concentrations; formulations were prepared once not more than 7 days prior to the study start and every 3 weeks thereafter for the 20-week study or monthly for the 27-week study (Table D2). The dose formulations were stored at room temperature for the 20-week study and for the 27-week study until April 6, 1999, or later, when formulations were stored at −20° C for up to 35 days.

Because the dose formulations were true solutions of the test article in ethanol, homogeneity studies were not performed. Prior to the 20-week study, a stability study of 2.19 mg/mL dose formulations of lot 01207BG was conducted by the study laboratory using GC by system G; stability was confirmed for up to 35 days for the dose formulation stored at ambient temperature in sealed containers under a nitrogen headspace and for up to 3 hours when exposed to light and air at ambient temperature.

Periodic analyses of the dose formulations of diisopropylcarbodiimide were conducted by the study laboratories using GC by system G. During the 20-week study, the dose formulations were analyzed four times; animal room samples of these dose formulations were also analyzed. All 20 dose formulations analyzed were within 10% of the target concentrations (Table D3); all 20 animal room samples analyzed were within 10% of the target concentrations. Dose formulations were analyzed four times during the 27-week study; animal room samples of these dose formulations were also analyzed (Table D4). Of the 20 dose formulations analyzed, all were within 10% of the target concentrations; 9 of 20 animal room samples were within 10% of the target concentrations. Unusual degradation was observed in the animal room samples from the formulations prepared on February 17, 1999, and June 7, 1999. Attempts to discover the cause of the degradation in the formulations were not conclusive, but the most likely cause, water in the anhydrous ethanol, was eliminated. To prevent degradation of the test chemical, formulations prepared on or after April 6, 1999, were stored at −20° C.

TABLE D1 Gas Chromatography Systems Used in the Dermal Studies of Diisopropylcarbodiimide^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Mass spectrometer | DB-5, 30 m × 0.25 mm, 0.25 μm (J&W Scientific, Folsom, CA) | Helium 40 cm^3^/second | 50° C, held for 5 minutes, then 10° C/minute to 250° C, held for 3 minutes
System B
Flame ionization | HP-1, 5 m × 0.53 mm, (Hewlett-Packard, Palo Alto, CA) | Nitrogen at 7 mL/minute | 35° C, then 10° C/minute to 185° C, held for 5 minutes
System C
Flame ionization | SPB-5, 30 m × 0.53 mm, 1 μm (Supelco, Bellefonte, PA) | Nitrogen at 7 mL/minute | 50° C, held for 5 minutes, then 10° C/minute to 250° C
System D
Flame ionization | Rtx-5, 30 m × 0.53 mm, 1.0 μm (Restek, Bellefonte, PA) | Helium at 10 mL/minute | 50° C, held for 5 minutes, then 10° C/minute to 250° C, held for 3 minutes
System E
Flame ionization | Rtx-5, 30 m × 0.53 mm, 1.0 μm (Restek) | Helium at 10 mL/minute | 70° C isothermal
System F
Flame ionization | Carbowax, 30 m × 0.53 mm, 1.2 μm (Alltech; Deerfield, Ill) | Nitrogen at 6 mL/minute | 40° C, held for 4 minutes, then 10° C/minute to 220° C
System G
Flame ionization | J&W DB-1, 30 m × 0.53 mm, 3 μm (J&W Scientific) | Nitrogen at 17.5 mL/minute | 115° C isothermal

a Gas chromatographs manufactured by Thermo Electron Corp. (Finnigan), San Jose, CA (system A), Hewlett-Packard, Palo Alto, CA (systems B, C, F, G), Varian, Palo Alto, CA (systems D, E); mass spectrometer was manufactured by Finnigan.

FIGURE D1 Infrared Absorption Spectrum of Diisopropylcarbodiimide

FIGURE D2 Proton Nuclear Magnetic Resonance Spectrum of Diisopropylcarbodiimide

TABLE D2 Preparation and Storage of Dose Formulations in the Dermal Studies of Diisopropylcarbodiimide

Tg.AC Hemizygous Mice 20-Week Study | p53 Haploinsufficient Mice 27-Week Study
Preparation
The first dose formulations were prepared in anhydrous ethanol no more than 7 days prior to study start, then every 3 weeks during the study. The highest dose formulation was prepared by weighing a specified amount of diisopropylcarbodiimide and dissolving in anhydrous ethanol to produce the appropriate concentration. Aliquots of this formulation were diluted with anhydrous ethanol to give the appropriate concentrations for the lower dose formulations. | Dose formulations were prepared every 4 weeks by weighing a specified amount of diisopropylcarbodiimide and adding anhydrous ethanol to produce the appropriate concentration for each dose formulation.
Chemical Lot Number
01207BG | 13016JS
Maximum Storage Time
35 days | 35 days
Storage Conditions
Aliquots of dose formulations were transferred to serum vials, crimp-sealed under a headspace of nitrogen gas, and stored at room temperature. | Aliquots of each dose level were transferred to serum vials, sealed under a headspace of inert gas, and stored at room temperature; formulations prepared on or after April 6, 1999, were stored at −20° C.
Study Laboratory
Microbiological Associates, Inc., Bethesda, MD | BioReliance Corporation, Rockville, MD

TABLE D3 Results of Analyses of Dose Formulations Administered to Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Diisopropylcarbodiimide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
June 8, 1995 | June 8, 1995 | 2.19 | 2.23 | +2
June 8, 1995 | June 8, 1995 | 4.38 | 4.35 | −1
June 8, 1995 | June 8, 1995 | 8.75 | 8.65 | −1
June 8, 1995 | June 8, 1995 | 17.5 | 16.9 | −3
June 8, 1995 | June 8, 1995 | 35.0 | 34.0 | −3
June 8, 1995 | July 7, 1995^b^ | 2.19 | 2.10 | −4
June 8, 1995 | July 7, 1995^b^ | 4.38 | 4.27 | −2
June 8, 1995 | July 7, 1995^b^ | 8.75 | 8.31 | −5
June 8, 1995 | July 7, 1995^b^ | 17.5 | 16.6 | −5
June 8, 1995 | July 7, 1995^b^ | 35.0 | 34.3 | −2
July 20, 1995 | July 20, 1995 | 2.19 | 2.29 | +5
July 20, 1995 | July 20, 1995 | 4.38 | 4.59 | +5
July 20, 1995 | July 20, 1995 | 8.75 | 8.63 | −1
July 20, 1995 | July 20, 1995 | 17.5 | 17.0 | −3
July 20, 1995 | July 20, 1995 | 35.0 | 34.9 | 0
July 20, 1995 | August 17, 1995^b^ | 2.19 | 2.27 | +4
July 20, 1995 | August 17, 1995^b^ | 4.38 | 4.52 | +3
July 20, 1995 | August 17, 1995^b^ | 8.75 | 8.59 | −2
July 20, 1995 | August 17, 1995^b^ | 17.5 | 16.9 | −3
July 20, 1995 | August 17, 1995^b^ | 35.0 | 34.6 | −1
August 31, 1995 | August 31, 1995 | 2.19 | 2.20 | 0
August 31, 1995 | August 31, 1995 | 4.38 | 4.43 | +1
August 31, 1995 | August 31, 1995 | 8.75 | 8.61 | −2
August 31, 1995 | August 31, 1995 | 17.5 | 17.6 | +1
August 31, 1995 | August 31, 1995 | 35.0 | 35.0 | 0
August 31, 1995 | September 28, 1995^b^ | 2.19 | 2.17 | −1
August 31, 1995 | September 28, 1995^b^ | 4.38 | 4.40 | 0
August 31, 1995 | September 28, 1995^b^ | 8.75 | 8.61 | −2
August 31, 1995 | September 28, 1995^b^ | 17.5 | 17.4 | −1
August 31, 1995 | September 28, 1995^b^ | 35.0 | 34.5 | −1
October 12, 1995 | October 12, 1995 | 2.19 | 2.18 | 0
October 12, 1995 | October 12, 1995 | 4.38 | 4.34 | −1
October 12, 1995 | October 12, 1995 | 8.75 | 8.55 | −2
October 12, 1995 | October 12, 1995 | 17.5 | 16.9 | −3
October 12, 1995 | October 12, 1995 | 35.0 | 34.2 | −2
October 12, 1995 | October 31, 1995^b^ | 2.19 | 1.87 | −15
October 12, 1995 | October 31, 1995^b^ | 4.38 | 4.36 | 0
October 12, 1995 | October 31, 1995^b^ | 8.75 | 8.50 | −3
October 12, 1995 | October 31, 1995^b^ | 17.5 | 17.2 | −2
October 12, 1995 | October 31, 1995^b^ | 35.0 | 34.1 | −3
October 12, 1995 | November 6, 1995^c^ | 2.19 | 2.29 | +5

a Results of duplicate analyses. Dosing volume=2.0 mL/kg; 2.19 mg/mL=4.38 mg/kg, 4.38 mg/mL=8.76 mg/kg, 8.75 mg/mL=17.5 mg/kg, 17.5 mg/mL=35 mg/kg, 35 mg/mL=70 mg/kg.

b Animal room samples

c Repeat analysis of 2.19 mg/kg animal room sample (October 31, 1995)

TABLE D4 Results of Analyses of Dose Formulations Administered to Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Diisopropylcarbodiimide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration ^a^ (mg/mL) | Difference from Target (%)
December 23, 1998 | December 23, 1998 | 2.19 | 2.22 | +1
December 23, 1998 | December 23, 1998 | 4.38 | 4.28 | −2
December 23, 1998 | December 23, 1998 | 8.75 | 8.54 | −2
December 23, 1998 | December 23, 1998 | 17.5 | 17.3 | −1
December 23, 1998 | December 23, 1998 | 35.0 | 33.5 | −4
December 23, 1998 | January 28, 1999^b^ | 2.19 | 2.00 | −9
December 23, 1998 | January 28, 1999^b^ | 4.38 | 3.82 | −13
December 23, 1998 | January 28, 1999^b^ | 8.75 | 7.83 | −10
December 23, 1998 | January 28, 1999^b^ | 17.5 | 16.0 | −9
December 23, 1998 | January 28, 1999^b^ | 35.0 | 32.8 | −6
February 17, 1999 | February 17, 1999 | 2.19 | 2.24 | +2
February 17, 1999 | February 17, 1999 | 4.38 | 4.39 | 0
February 17, 1999 | February 17, 1999 | 8.75 | 9.19 | +5
February 17, 1999 | February 17, 1999 | 17.5 | 17.9 | +2
February 17, 1999 | February 17, 1999 | 35.0 | 35.3 | +1
February 17, 1999 | March 25, 1999^b^ | 2.19 | 0.47 | −78
February 17, 1999 | March 25, 1999^b^ | 4.38 | 0.28 | −94
February 17, 1999 | March 25, 1999^b^ | 8.75 | 0.27 | −97
February 17, 1999 | March 25, 1999^b^ | 17.5 | 4.0 | −77
February 17, 1999 | March 25, 1999^b^ | 35.0 | 16.0 | −54
April 6, 1999 | April 6, 1999 | 2.19 | 2.11 | −4
April 6, 1999 | April 6, 1999 | 4.38 | 4.32 | −1
April 6, 1999 | April 6, 1999 | 8.75 | 8.65 | −1
April 6, 1999 | April 6, 1999 | 17.5 | 17.1 | −2
April 6, 1999 | April 6, 1999 | 35.0 | 34.4 | −2
April 6, 1999 | May 6, 1999^b^ | 2.19 | 1.97 | −10
April 6, 1999 | May 6, 1999^b^ | 4.38 | 4.11 | −5
April 6, 1999 | May 6, 1999^b^ | 8.75 | 8.05 | −7
April 6, 1999 | May 6, 1999^b^ | 17.5 | 17.7 | +1
April 6, 1999 | May 6, 1999^b^ | 35.0 | 34.1 | −3
June 7, 1999 | June 7, 1999 | 2.19 | 2.27 | +4
June 7, 1999 | June 7, 1999 | 4.38 | 4.34 | −1
June 7, 1999 | June 7, 1999 | 8.75 | 8.60 | −2
June 7, 1999 | June 7, 1999 | 17.5 | 17.2 | −2
June 7, 1999 | June 7, 1999 | 35.0 | 34.2 | −2
June 7, 1999 | July 13, 1999^b^ | 2.19 | 1.72 | −22
June 7, 1999 | July 13, 1999^b^ | 4.38 | 3.44 | −23
June 7, 1999 | July 13, 1999^b^ | 8.75 | 7.22 | −17
June 7, 1999 | July 13, 1999^b^ | 17.5 | 13.7 | −23
June 7, 1999 | July 13, 1999^b^ | 35.0 | 28.3 | −23

a Results of duplicate analyses. Dosing volume=2.0 mL/kg; 2.19 mg/mL=4.38 mg/kg, 4.38 mg/mL=8.76 mg/kg, 8.75 mg/mL=17.5 mg/kg, 17.5 mg/mL=35 mg/kg, 35 mg/mL=70 mg/kg.

b Animal room samples