# APPENDIX C ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE C1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Diisopropylcarbodiimide^a^

| Vehicle Control | 4.38 mg/kg | 8.75 mg/kg | 17.5 mg/kg | 35 mg/kg | 70 mg/kg
n | 8 | 8 | 8 | 8 | 6 | 1 0
Necropsy body wt | 27.8 ± 0.5 | 29.1 ± 1.6 | 30.0 ± 2.7 | 26.9 ± 1.0 | 26.0 ± 1.4 | 25.6 ± 0.5
Heart
Absolute | 0.142 ± 0.005 | 0.144 ± 0.004 | 0.149 ± 0.007 | 0.142 ± 0.003 | 0.132 ± 0.008 | 0.135 ± 0.003
Relative | 5.113 ± 0.144 | 5.031 ± 0.205 | 5.087 ± 0.305 | 5.296 ± 0.137 | 5.083 ± 0.136 | 5.274 ± 0.131
R. Kidney
Absolute | 0.235 ± 0.011 | 0.233 ± 0.007 | 0.243 ± 0.015 | 0.235 ± 0.008 | 0.218 ± 0.011 | 0.220 ± 0.006
Relative | 8.453 ± 0.328 | 8.108 ± 0.249 | 8.260 ± 0.472 | 8.790 ± 0.395 | 8.427 ± 0.252 | 8.597 ± 0.216
Liver
Absolute | 1.536 ± 0.080^b^ | 1.637 ± 0.081 | 1.769 ± 0.135 | 1.593 ± 0.057 | 1.555 ± 0.088 | 1.428 ± 0.032
Relative | 55.278 ± 2.147^b^ | 56.534 ± 1.411 | 59.502 ± 2.645 | 59.658 ± 2.758 | 59.950 ± 1.781 | 55.828 ± 1.106
Lung
Absolute | 0.198 ± 0.008 | 0.196 ± 0.006 | 0.229 ± 0.018 | 0.212 ± 0.018 | 0.195 ± 0.009 | 0.175 ± 0.008
Relative | 7.122 ± 0.289 | 6.852 ± 0.400 | 7.811 ± 0.607 | 8.021 ± 0.879 | 7.591 ± 0.403 | 6.858 ± 0.342
Thymus
Absolute | 0.036 ± 0.003 | 0.044 ± 0.002 | 0.038 ± 0.004 | 0.036 ± 0.003 | 0.032 ± 0.002 | 0.035 ± 0.002
Relative | 1.277 ± 0.097 | 1.524 ± 0.044 | 1.251 ± 0.075 | 1.338 ± 0.122 | 1.249 ± 0.072 | 1.364 ± 0.086

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Differences from the vehicle control group are not significant by Dunnett’s test.

b n=7